# Peer Review

The draft NTP Immunotoxicity Technical Report on the Dermal Hypersensitivity and Irritancy Studies of 4-Methylcyclohexanemethanol (CASRN 34885-03-5) and Crude 4-Methylcyclohexanemethanol Administered Topically to Female BALB/c Mice was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of these NTP studies were appropriate and ensured that this Immunotoxicity Report presents the experimental results and conclusions fully and clearly.

## Peer Reviewers

- Anne Marie Api, Ph.D.
  Vice President, Human Health Sciences, Research Institute for Fragrance Materials, Inc. (RIFM)
  Woodcliff Lake, New Jersey, USA
- Joan Chapdelaine Ph.D.
  Principal Owner/Consultant, Chapdelaine Consulting, LLC
  Tunkhannock, Pennsylvania, USA