# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  K.A. Shipkowski, Ph.D., Study Scientist
  S.S. Auerbach, Ph.D.
  C.R. Blystone, Ph.D.
  B.J. Collins, M.S.P.H.
  J.M. Fostel, Ph.D.
  P.M. Foster, Ph.D.
  D.R. Germolec, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  S.A. Masten, Ph.D.
  K.R. Shockley, Ph.D.
  M.D. Stout, Ph.D.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
- Burleson Research Technologies, Inc., Cary, North Carolina, USA
  Conducted studies and evaluated findings
  V.J. Johnson, Ph.D., Principal Investigator
  F.G. Burleson, Ph.D.
  G.R. Burleson, Ph.D.