# References

1 Lide DR Milne GWA No. 2228. Vol. I. 3rd ed. Boca Raton (FL): CRC Press, Inc.; 1994. (Handbook of data on organic compounds.).
2 United States Environmental Protection Agency (USEPA). Estimation Programs Interface Suite™ for Microsoft Windows©, Ver. 4.1. Washington, DC: United States Environmental Protection Agency; 2014. https://www.epa.gov/tsca-screening-tools/estimation-program-interface-epi-suite-tm-program-modifications-new-features
3 Eastman Chemical Company Safety data sheet: Crude MCHM, version 3.0. Kingsport (TN): Eastman Chemical Company; 2015.
4 Foreman WT Rose DL Chambers DB Crain AS Murtagh LK Thakellapalli H Wang KK Determination of (4-methylcyclohexyl) methanol isomers by heated purge-and-trap GC/MS in water samples from the 2014 Elk River, West Virginia, chemical spill. Chemosphere. 2015;131:217–224. 10.1016/j.chemosphere.2014.11.006 25542639
5 Gallagher DL Phetxumphou K Smiley E Dietrich AM Tale of two isomers: complexities of human odor perception for cis-and trans-4-methylcyclohexane methanol from the chemical spill in West Virginia. Environ Sci Technol. 2015;49(3):1319–1327. 10.1021/es5049418 25541902
6 National Library of Medicine (NLM). ChemIDplus: 4-methoxymethylcyclohexylmethanol. Bethesda, MD: U.S. Department of Health and Human Services, National Institutes of Health, National Library of Medicine, Toxicology Data Network; 2016. https://chem.nlm.nih.gov/chemidplus/rn/98955-27-2 [Accessed: September 21, 2016]
7 National Library of Medicine (NLM). ChemIDplus: Methyl 4 methylcyclo-hexanecarboxylate. Bethesda, MD: U.S. Department of Health and Human Services, National Institutes of Health, National Library of Medicine, Toxicology Data Network; 2016. https://chem.nlm.nih.gov/chemidplus/rn/51181-40-9 [Accessed: September 21, 2016]
8 Eastman Chemical Company Technical data sheet: Eastman™ DMCD. Kingsport (TN): Eastman Chemical Company; 2008.
9 Eastman Chemical Company Technical data sheet: Eastman™ CHDM-D, CAS No. 105-08-8.1,4-cyclohexanedimethanol. Kingsport (TN): Eastman Chemical Company; 2008.
10 West Virginia Office of the Governor. After action review: Emergency response to January 9, 2014, Freedom Industries chemical leak. Charleston, WV: State of West Virginia, Office of the Governor, Homeland Security and Emergency Management & West Virginia National Guard; 2015. http://governor.wv.gov/Documents/After%20Action%20Review.PDF [Accessed: September 21, 2016]
11 West Virginia Poison Center (WVPC). Factsheet: Freedom Industries, Elk River chemical spill, February 10, 2014. Washington, DC: West Virginia Poison Center & Georgetown University, Mid-Atlantic Center for Children’s Health and the Environment; 2014. http://www.wvlegislature.gov/legisdocs/2014/committee/interim/water/Documents/Bureau%20for%20Public%20Health%20Packet.pdf [Accessed: September 21, 2016]
12 Centers for Disease Control Prevention (CDC). Summary report of short-term screening level calculation and analysis of available animal studies for MCHM. Atlanta, GA: U.S. Department of Health and Human Services, Public Health Service, Centers for Disease Control and Prevention; 2014. https://emergency.cdc.gov/chemical/MCHM/westvirginia2014/mchm.asp [Accessed: September 21, 2016]
13 Whelton AJ McMillan L Connell M Kelley KM Gill JP White KD Gupta R Dey R Novy C Residential tap water contamination following the Freedom Industries chemical spill: Perceptions, water quality, and health impacts. Environ Sci Technol. 2015;49(2):813–823. 10.1021/es5040969 25513829
14 Toxicology Excellence for Risk Assessment (TERA). Report of expert panel review of screening levels for exposure to chemicals from the January 2014 Elk River spill. Charleston, WV: Toxicology Excellence for Risk Assessment & West Virginia Division of Homeland Security and Emergency Management, West Virginia Testing Assessment Project (WV TAP); 2014.
15 DiVincenzo GD Ziegler DA Metabolic fate of 1, 4-cyclo [14C] hexanedimethanol in rats. Toxicol Appl Pharmacol. 1980;52(1):10–15. 10.1016/0041-008X(80)90241-0 7361305
16 Eastman Kodak Company. Acute toxicity of 4-methylcyclohexane methanol. Rochester, NY: Eastman Kodak Company, Health and Environment Laboratory, Toxicological Sciences Laboratory; 1990. TX-90-5; HAEL No. 89 0081; Accession No. 907670. https://www.eastman.com/Literature_Center/Misc/Pure_Distilled_MCHM-Acute_Toxicity_Battery_Containing_5_Study_Reports.pdf
17 Eastman Kodak Company. Four-week oral toxicity study of 4-methylcyclohexane methanol in the rat. Rochester, NY: Eastman Kodak Company, Health and Environment Laboratory, Toxicological Sciences Laboratory; 1990. TX-89-296; HAEL No. 89-0081; Accession. No. 907670. https://www.eastman.com/Literature_Center/Misc/Pure_Distilled_MCHM-28-Day_Oral_Feeding_Study.pdf
18 Eastman Kodak Company. Crude MCHM: Acute dermal toxicity study in the rat (final report). Rochester, NY: Eastman Kodak Company, Health and Environment Laboratory, Toxicological Sciences Laboratory; 1998. TX-97-308; HAEL No. 97-0216; EAN 972790; PM No. 19717-00. https://www.eastman.com/Literature_Center/Misc/Crude_MCHM-Acute_Dermal_Toxicity_Study.pdf
19 Eastman Kodak Company. Crude MCHM: Acute oral toxicity study in the rat – first study (final report). Rochester, NY: Eastman Kodak Company, Health and Environment Laboratory, Toxicological Sciences Laboratory; 1998. TX-97-306; HAEL No. 97-0216; EAN 972790; PM No. 18717-00. https://www.eastman.com/Literature_Center/Misc/Crude_MCHM-First_Acute_Oral_Study.pdf
20 Eastman Kodak Company. Crude MCHM: Acute oral toxicity study in the rat – second study (final report). Rochester, NY: Eastman Kodak Company, Health and Environment Laboratory, Toxicological Sciences Laboratory; 1999. TX-99-188; HAEL No. 97-0216; EAN 972790; PM No. 18717-00. https://www.eastman.com/Literature_Center/Misc/Crude_MCHM-Second_Acute_Oral_Study.pdf
21 United States Environmental Protection Agency (USEPA). High Production Volume Information System (HPVIS) for 1,4-cyclohexanedicarboxylic acid, dimethyl ester (CAS No. 94-60-0). Washington, DC: United States Environmental Protection Agency; 2016. https://ofmpub.epa.gov/oppthpv/quicksearch.display?pChem=101465 [Accessed: September 21, 2016]
22 Eastman Chemical Company Safety data sheet: Eastman™ DMCD, version 2.1. Kingsport (TN): Eastman Chemical Company; 2016.
23 United States Environmental Protection Agency (USEPA) Screening-level hazard characterization for high production volume chemicals: 1,4-cyclohexanedimethanol (CAS No. 105-08-8) 9th CI Name; 1,4 cyclohexanemethanol. Washington (DC): United States Environmental Protection Agency, Office of Pollution Prevention and Toxics, High Production Volume Chemicals Branch, Risk Assessment Division; 2007.
24 Schade CP Wright N Gupta R Latif DA Jha A Robinson J Self-reported household impacts of large-scale chemical contamination of the public water supply, Charleston, West Virginia, USA. PLoS One. 2015;10(5):e0126744. 10.1371/journal.pone.0126744 25951197
25 Eastman Kodak Company. Crude MCHM: Acute dermal irritation study in the rabbit (final report). Rochester, NY: Eastman Kodak Company, Health and Environment Laboratory, Toxicological Sciences Laboratory; 1997. TX-97-256; HAEL No. 97-0216; EAN 972790; PM No. 18717-00. https://www.eastman.com/Literature_Center/Misc/Crude_MCHM-Skin_Irritation_Study.pdf
26 Eastman Kodak Company. Crude MCHM: A two-week dermal toxicity study in the rat (final report). Rochester, NY: Eastman Kodak Company, Health and Environment Laboratory, Toxicological Sciences Laboratory; 1999. TX-98-129; HAEL No. 7-0216; EAN 972790; PM No. 18717-00. https://www.eastman.com/Literature_Center/Misc/Crude_MCHM-14-Day_Dermal_Study.pdf
27 Eastman Kodak Company. Crude MCHM: Skin sensitization study (footpad method) in the guinea pig (final report). Rochester, NY: Eastman Kodak Company, Health and Environment Laboratory, Toxicological Sciences Laboratory; 1997. TX-97-271; HAEL No. 97-0216; EAN 972790; PM No. 18717-00. https://www.eastman.com/Literature_Center/Misc/Crude_MCHM-Skin_Sensitization.pdf
28 National Toxicology Program (NTP). NTP update: West Virginia chemical spill: High throughput screening assays. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2014. https://ntp.niehs.nih.gov/ntp/research/areas/wvspill/hts_wvupdate_508.pdf [Accessed: September 21, 2016]
29 Woolhiser MR Munson AE Meade BJ Comparison of mouse strains using the local lymph node assay. Toxicology. 2000;146(2-3):221–227. 10.1016/s0300-483x(00)00152-9 10814854
30 Hou F Xing C Li B Cheng J Chen W Zhang M Application of BALB/c mouse in the local lymph node assay:BrdU-ELISA for the prediction of the skin sensitizing potential of chemicals. J Pharmacol Toxicol Methods. 2015;72:53–58. 10.1016/j.vascn.2015.01.001 25600862
31 Lee YS, Yi JS, Seo SJ, Kim JH, Jung MS, Seo IK, Ahn I, Ko K, Kim TS, Lim KM, et al. Comparison of BALB/c and CBA/J mice for the local lymph node assay using bromodeoxyuridine with flow cytometry (LLNA: BrdU-FCM). Regul Toxicol Pharm. 2017; 83:13-22. 10.1016/j.yrtph.2016.10.021
32 Gerberick GF Robinson MK Ryan CA Dearman RJ Kimber I Basketter DA Wright Z Marks JG Contact allergenic potency: correlation of human and local lymph node assay data. Am J Contact Dermat. 2001;12(3):156–161. 11526521
33 International Coordinating Committee on the Validation of Alternative Methods (ICCVAM). Recommended performance standards: Murine local lymph node assay. Research Triangle Park, NC: National Institutes of Health, National Institute of Environmental Health Sciences; 2009. NIH Publication No. 09-7357.
34 International Coordinating Committee on the Validation of Alternative Methods (ICCVAM). ICCVAM test method evaluation report: Usefulness and limitations of the murine local lymph node assay for potency categorization of chemicals causing allergic contact dermatitis in humans. Research Triangle Park, NC: National Institutes of Health, National Institute of Environmental Health Sciences; 2011. NIH Publication No. 11-7709.
35 Kimber I Basketter DA Berthold K Butler M Garrigue JL Lea L Newsome C Roggeband R Steiling W Stropp G Skin sensitization testing in potency and risk assessment. Toxicol Sci. 2001;59(2):198–208. 10.1093/toxsci/59.2.198 11158712
36 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50(272):1096–1121.10.1080/01621459.1955.10501294
37 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971;27:103–117. 10.2307/2528930 5547548
38 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972;28:519–531. 10.2307/2556164 5037867
39 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977;33:386–389. 10.2307/2529789 884197
40 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986;42:183–186. 10.2307/2531254 3719054
41 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964;6(3):241–252.10.1080/00401706.1964.10490181
42 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41(1/2):133–145.10.2307/2333011
43 Dixon WJ Massey FJ Jr Introduction to statistical analysis. 2nd ed. New York: McGraw-Hill Book Company, Inc.; 1957. p. 276–278, 412.
44 Code of Federal Regulations (CFR). 21:Part 58.
45 National Toxicology Program (NTP). IMM-01: Data. Research Triangle Park, NC; 2020. 10.22427/NTP-DATA-IMM-01
46 Occupational Safety and Health Administration (OSHA) Globally harmonized system of classification and labelling of chemicals. 2015. https://www.osha.gov/dsg/hazcom/gbsguideoct05.pdf
47 National Toxicology Program (NTP). West Virginia chemical spill, structure-activity relationship analysis, supporting data files. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2016. https://tools.niehs.nih.gov//cebs3/wvspill
48 Dearman RJ, Basketter DA, Kimber I. Local lymph node assay: Use in hazard and risk assessment. J Appl Toxicol. 1999; 19(5):299-306. 10.1002/(SICI)1099-1263(199909/10)19:5<299::AID-JAT591>3.0.CO;2-C
49 Hoffmann S LLNA variability: an essential ingredient for a comprehensive assessment of non-animal skin sensitization test methods and strategies. ALTEX. 2015;32(4):379–383. 26168096
50 Advanced Chemistry Development Inc. SciFinder® Spectrum ID 34885035-HNMR. Predicted NMR data calculated using Advanced Chemistry Development, Inc., software V11.01. Toronto, Ontario, Canada; 1994.
51 National Institute of Standards and Technology (NIST). Mass spectral library. Gaithersburg, MD: National Institute of Standards and Technology; 2008. Version d.0F; trans: ID 18215, cis: ID 18228.
52 American Chemical Society (ACS). SciFinder® Spectrum ID BR089294. 2014.
53 American Chemical Society (ACS). SciFinder® Spectrum ID NC_05067. 2014.
54 Allen CFH Ball WL Young DM Dihydro-p-tolualdehyde. Can J Res. 1933;9(2):169–174.10.1139/cjr33-078
55 Advanced Chemistry Development Inc. ACD/ChemSketch v. 10.01, ACD/SpecManager v. 10.02. ACD/C+H NMR Predictors and DB v. 10.02, and ACD/PhysChem Database v. 10.01. Toronto, Ontario, Canada: ACD/Labs.
56 National Institute of Standards and Technology (NIST). Wiley Registry: Mass spectral library. Gaithersburg, MD: National Institute of Standards and Technology; 2005. Version G1035B/Rev. D.06.00, Entry Nos. 339581, 339455, 338455.
57 National Institute of Advanced Industrial Science and Technology (NIAIST). SDBS No. 16005, IR-NIDA-00569. 2016. https://sdbs.db.aist.go.jp/sdbs/ [Accessed: February 9, 2016]
58 National Institute of Advanced Industrial Science and Technology (NIAIST). SDBS No. 16005, HSP-42-796. 2016. https://sdbs.db.aist.go.jp/sdbs [Accessed: February 9, 2016]
59 National Institute of Advanced Industrial Science and Technology (NIAIST). SDBS No. 16005, CDS-02-723. 2016. https://sdbs.db.aist.go.jp/sdbs/ [Accessed: February 9, 2016]
60 Sigma-Aldrich library 2014. https://www.sigmaaldrich.com/spectra/fnmr/FNMR010098.pdf
61 National Institute of Advanced Industrial Science and Technology (NIAIST). SDBS No. 10307, IR-NIDA-64369. 2010. https://sdbs.db.aist.go.jp/sdbs/ [Accessed: May 25, 2010]