# Discussion

The primary concern for human exposure to 4-methylcyclohexanemethanol (MCHM) is via occupational routes, primarily during handling or use of the chemical. However, on January 9, 2014, approximately 10,000 gallons of a chemical mixture containing predominantly MCHM was spilled into the Elk River, upstream of a municipal water source serving approximately 300,000 people in Charleston, West Virginia.^10^ Immediately following the spill, there were numerous reports of mild rashes and reddened skin due to dermal exposure to the contaminated water.^24^ Following nominations by the Centers for Disease Control and Prevention and the Agency for Toxic Substances and Disease Registry, the National Toxicology Program (NTP) conducted dermal hypersensitivity and irritancy studies of both MCHM and crude MCHM in female BALB/c mice.

In the initial study, MCHM (2%, 20%, and 100%) and crude MCHM (1%, 2%, 5%, 20%, 40%, and 100%) formulations were applied to the ears of female BALB/c mice for 3 consecutive days via direct epicutaneous application. Two mice administered 100% MCHM were euthanized moribund on day 1 of the study due to signs of morbidity, and the dose was subsequently lowered to 50%. Also, due to clinical signs of toxicity in mice administered 100% MCHM, this dose was lowered to 80%. A repeat study of crude MCHM was performed to confirm the observed dermal hypersensitivity response and more clearly establish levels at which the test article induced sensitization in the absence of clinical toxicity. Formulations of 1%, 5%, 25%, 50%, and 75% crude MCHM were utilized in the repeat study.

MCHM induced dermal irritation at concentrations greater than 20%. Administration of 20% and 100/50% MCHM induced significant concentration-dependent increases in mean ear thickness on day 3 (4.44% and 6.47%, respectively) and day 6 (3.54% and 5.30%, respectively). For crude MCHM, there was minimal evidence of irritation and the results were inconsistent between studies. In the initial study a statistically significant increase in irritation was observed on day 6 in the 20% group only (3.86%) and not at doses of 40 or 100/80%. In the repeat study significant changes in ear thickness occurred only at 75%, with no evidence of a concentration-dependent response. The results from these studies indicate that MCHM should be considered a dermal irritant on the basis of the Globally Harmonized System of Classification and Labelling of Chemicals.^46^ These results are consistent with those from studies previously conducted by Eastman Kodak Company, which demonstrated that topical administration of MCHM and crude MCHM caused strong dermal irritation in guinea pigs (MCHM), albino rabbits (crude MCHM), and rats (crude MCHM).^16,18,25-27^ The results of the studies described in this Immunotoxicity Report suggest that MCHM is likely a more potent irritant than crude MCHM. These results also suggest that MCHM itself, and not the other chemicals found in crude MCHM, was responsible for the dermal irritation reported following the Elk River spill.

The local lymph node assay (LLNA) is the standard assay for evaluating the potential of a compound to act as a skin sensitizer.^32-34^ Skin sensitization potential is assessed as a measurement of lymph node cell proliferation in response to application of the compound in question, and a compound is classified as a skin sensitizer if one or more concentrations causes a threefold or greater increase in lymph node cell proliferation relative to vehicle control (stimulation index [SI] ≥ 3); the effective concentration of a compound that induces an SI equal to 3 is known as the EC3. In these studies, crude MCHM was determined to be a sensitizer, with an EC3 in the concentration range of 35% to 60%. This is in contrast to sensitization results using the guinea pig footpad test and previously reported by Eastman Kodak Company^27^; however, this is likely due to the difference in testing methodologies.

MCHM was not deemed to be a skin sensitizer in these studies. These results suggest that although MCHM is a dermal irritant, other chemical components of crude MCHM are likely responsible for the observed stimulation in the LLNA. This is supported by results from structure-activity relationship analyses performed by NTP that indicated some of the minor components of crude MCHM were potential sensitizers.^47^ Inconsistencies were observed in the studies of crude MCHM. In the initial study, administration of 20% crude MCHM significantly increased ear swelling, whereas administration of 50% crude MCHM did not. The lack of a concentration-dependent trend suggests that the effects observed at 20% MCHM might not have been treatment related. Similarly, in the repeat study of crude MCHM, treatment with 75% crude MCHM significantly increased ear swelling but treatment with other concentrations did not. It has been reported that dermal irritants could also induce lymph node cell proliferation, possibly resulting in false positives in the LLNA^32,33,48^; however, the irritancy responses were not considered to be strong enough to cause additional proliferation in the draining lymph nodes, and, therefore, support the identification of crude MCHM as a skin sensitizer.

A decrease in the SI was observed following treatment with MCHM (2%, 20%, and 100/50%) relative to vehicle control; this decrease was significant in the 2% MCHM group and lessened with increasing MCHM concentration. The SI value for the vehicle control animals (1.00 ± 0.22) was similar to that of the vehicle controls for the repeat study of crude MCHM (1.00 ± 0.24), indicating that the vehicle was likely not the reason for the observed decrease in SI. The reason for the low SI values in mice treated with MCHM is unclear; however, it could be due to the weak sensitizing ability of MCHM as only crude MCHM was determined to be a skin sensitizer in these studies.

Two positive controls were used in this study, 1-fluoro-2,4-dinitrobenzene and isoeugenol. 1-Fluoro-2,4-dinitrobenzene and isoeugenol are standard positive controls for dermal hypersensitivity and irritancy studies, with 1-fluoro-2,4-dinitrobenzene acting as a strong sensitizer and isoeugenol acting as a weak sensitizer. In these studies, 1-fluoro-2,4-dinitrobenzene performed as expected; however, isoeugenol did not elicit the anticipated sensitizing response. SI and EC3 values for the different categories of sensitizers (nonsensitizing, weak, moderate, strong, and extreme) have a wide range^49^ and SI values for isoeugenol, in particular, are historically variable. Despite the unexpected weak response of isoeugenol, the SI values for 1-fluoro-2,4-dinitrobenzene (10.02 and 76.02) and isoeugenol (1.64) fell within the ranges of historical values for both the NTP’s and the study laboratory’s designations of potent and weak sensitizers. In addition, as both the crude MCHM and 1-fluoro-2,4-dinitrobenzene LLNA results were repeated, the lack of response from isoeugenol was considered an isolated result.

The results of these studies indicate that the estimated lowest-observed-effect levels for MCHM (20% based on irritancy) and crude MCHM (5% based on dermal sensitization) were significantly higher than those levels found in the area’s residential tap water immediately following the Elk River spill (up to 3.35 ppm), which, in turn, were higher than that of the Centers for Disease Control and Prevention’s short-term drinking water screening level of 1 ppm.^12^ Despite the low levels of MCHM detected in the area’s tap water following the spill, reports of dermal irritation were increased in the population using the contaminated water. The dosing pattern utilized in the studies reported here was a single, daily administration, whereas the pattern of human exposure following the spill was potentially more extensive due to daily showering, bathing, and hand washing habits.

Under the conditions of these dermal hypersensitivity and irritancy studies, MCHM induced dermal irritation in female mice, as indicated by increases in ear swelling at concentrations of 20% and 100/50%. Crude MCHM was identified as a skin sensitizer, with an EC3 value in the concentration range of 35% to 60%. Dermal exposure to crude MCHM produced minimal irritant effects, indicated by increases in ear swelling at concentrations of 20% and 75%, which were inconsistent across repeat studies.