# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-IMM-01.^45^

## 4-Methylcyclohexanemethanol

4-Methylcyclohexanemethanol (MHCM) was initially tested at concentrations of 2%, 20%, and 100%. All mice administered 2% or 20% survived to the end of the study with no clinical observations of toxicity (Table 4, Table 5, and Table 6). Mice in the 100% group demonstrated signs of morbidity on day 1, including eye squinting, hypoactivity, hunched posture, and isolation from cage mates, resulting in two mice being euthanized moribund (Table 6). Consequently, the 100% dose was lowered to 50% on days 2 and 3 (this group is referred to hereafter as the 100/50% group). Clinical observations noted in surviving 100/50% mice included eye squinting and hypoactivity, albeit to a lesser extent than was observed prior to lowering the 100% dose. All clinical signs were observed during the afternoon observation period after treatment, but none was observed during morning observation the subsequent day. Group mean body weights were not significantly affected by treatment (Table 5).

Table 4 Disposition of Female Mice in the Dermal Hypersensitivity and Irritancy Study of 4-Methylcyclohexanemethanol

| Vehicle Control | 2% | 20% | 100/50% | 0.15% DNFB | 5% ISO^a^
Animals Initially in Study | 5 | 5 | 5 | 5 | 5 | 5
Euthanized Moribund | 0 | 0 | 0 | 2 | 0 | 0
Terminal Removal | 5 | 5 | 5 | 3 | 5 | 5

DNFB = 1-fluoro-2,4-dinitrobenzene; ISO = isoeugenol.

^a^ Positive control.

Table 5 Survival and Mean Body Weights of Female Mice in the Dermal Hypersensitivity and Irritancy Study of 4-Methylcyclohexanemethanol^a^

Concentration | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Absolute Weight Gain or Loss
Vehicle Control | 5/5 | 17.2 ± 0.6 | 17.9 ± 0.6 | 0.7 ± 0.2
2% | 5/5 | 17.3 ± 0.6 | 18.0 ± 0.7 | 0.7 ± 0.2
20% | 5/5 | 17.9 ± 0.6 | 18.1 ± 0.5 | 0.2 ± 0.2
100/50% | 3/5^d^ | 17.3 ± 0.6 | 18.4 ± 0.5 | 0.6 ± 0.2
0.15% DNFB^c^ | 5/5 | 17.4 ± 0.6 | 18.3 ± 0.7 | 0.9 ± 0.3
5% ISO | 5/5 | 17.0 ± 0.4 | 17.5 ± 0.3 | 0.5 ± 0.2

DNFB = 1-fluoro-2,4-dinitrobenzene; ISO = isoeugenol.

^a^ Weights are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study.

^b^ Number of animals surviving on day 6/number initially in group.

^c^ Positive control.

^d^ Two moribund animals were removed on study day 1.

Table 6 Clinical Observations for Female Mice in the Dermal Hypersensitivity and Irritancy Study of 4-Methylcyclohexanemethanol

| Vehicle Control | 2% | 20% | 100/50% | 0.15% DNFB^b^ | 5% ISO^c^
n | 5 | 5 | 5 | 5 | 5 | 5
Animal Behavior, Isolation^a^ | 0 | 0 | 0 | 5 (1) | 5 (1) | 0
Erythema, Ear, Bilateral, Mild | 0 | 0 | 0 | 0 | 5 (4) | 0
Erythema, Ear, Bilateral, Moderate | 0 | 0 | 0 | 0 | 5 (3) | 0
Eye Shut, Bilateral | 0 | 0 | 0 | 5 (1) | 5 (1) | 0
Hunched | 0 | 0 | 0 | 2 (1) | 0 | 0
Hypoactivity | 0 | 0 | 0 | 5 (1) | 5 (3) | 0

DNFB = 1-fluoro-2,4-dinitrobenzene; ISO = isoeugenol.

^a^ Number of animals with observation (study day first observed).

^b^ Positive control.

^c^ Positive control (did not perform as expected).

The irritancy properties of MCHM were assessed by evaluating changes in ear swelling, which were determined by measuring treatment-related changes in ear thickness, relative to vehicle control animals. Treatment resulted in concentration-dependent increases in mean ear thickness in the 20% and 100/50% groups on day 3 (4.44% and 6.47%, respectively) and day 6 (3.54% and 5.30%, respectively), relative to the vehicle control (Table 7).

Table 7 Summary of Ear Thickness Measurement Data for Female Mice in the Dermal Hypersensitivity and Irritancy Study of 4-Methylcyclohexanemethanol^a^

Concentration | Day 1 (mm × 10^−2^) | Day 3 (mm × 10^−2^) | Day 6 (mm × 10^−2^) | Day 3 (%) | Day 6 (%) | Ear Weight (mg)
Vehicle Control | 15.58 ± 0.17 (5) | 15.66 ± 0.14^▲▲^ (5) | 15.56 ± 0.12^▲▲^ (5) | −0.04 ± 0.96^▲▲^ (5) | 0.02 ± 0.78^▲▲^ (5) | 7.78 ± 0.42 (5)
2% | 15.52 ± 0.08 (5) | 15.98 ± 0.02 (5) | 15.62 ± 0.07 (5) | 2.04 ± 0.16 (5) | 0.34 ± 0.39 (5) | 8.94 ± 0.38 (5)
20% | 15.60 ± 0.10 (5) | 16.34 ± 0.12** (5) | 16.10 ± 0.10** (5) | 4.44 ± 0.78** (5) | 3.54 ± 0.64** (5) | 8.62 ± 0.11 (5)
100/50% | 15.56 ± 0.06 (5) | 16.67 ± 0.33** (3) | 16.40 ± 0.06** (3) | 6.47 ± 2.13** (3) | 5.30 ± 0.46** (3) | 8.57 ± 0.64 (3)
0.15% DNFB^b^ | 15.34 ± 0.04 (5) | 16.94 ± 0.13** (5) | 16.98 ± 0.09** (5) | 8.12 ± 0.78** (5) | 8.98 ± 0.60** (5) | 11.60 ± 0.79** (5)
5% ISO^b^ | 15.40 ± 0.10 (5) | 16.92 ± 0.05** (5) | 16.60 ± 0.19* (5) | 7.96 ± 0.39** (5) | 6.74 ± 1.20* (5) | 8.10 ± 1.02 (5)

^▲▲^Significant trend (p ≤ 0.01) by Jonckheere’s test.

* Significantly different (p ≤ 0.05) from the vehicle control group by Shirley’s or Dunn’s test.

** p ≤ 0.01.

DNFB = 1-fluoro-2,4-dinitrobenzene; ISO = isoeugenol.

^a^ Ear thickness data are presented as mean ± standard error (n); percentages are calculated as ear swelling (difference from vehicle control) using the equation: [mean measurement for both ears for each animal (day 3 or 6) − vehicle control mean ear thickness (day 3 or 6)]/[vehicle control mean ear thickness (day 3 or 6) × 100].

^b^ Positive control.

The local lymph node assay (LLNA) was used to evaluate the ability of MCHM to induce dermal sensitization. The LLNA uses incorporation of ^125^I-iododeoxyuridine (^125^I-UdR) as a measure of DNA synthesis and lymphocyte proliferation. On day 6, 3 days after final dosing, mice were injected intravenously with ^125^I-UdR and rested for 5 hours to allow for incorporation of the labeled material into proliferating cells in the draining lymph nodes. Treatment with MCHM did not significantly modulate mean group disintegrations per minute (DPM) compared to that of the vehicle control group or the stimulation index (SI; treated group mean DPM/vehicle control group mean DPM) values (Table 8 and Figure 2). No EC3 value was calculated for MCHM as all SI values were below 3.

Table 8 Summary of ^125^I-UdR Incorporation and Stimulation Index Data for Female Mice in the Dermal Hypersensitivity and Irritancy Study of 4-Methylcyclohexanemethanol^a^

Concentration | n | Lymph Node Counts (DPM) | Stimulation Index
Vehicle Control | 5 | 20.76 ± 4.67 | 1.00 ± 0.22
2% | 5 | 2.33 ± 0.97** | 0.11 ± 0.05**
20% | 5 | 5.86 ± 1.33 | 0.28 ± 0.06
100/50% | 3 | 18.39 ± 6.10 | 0.88 ± 0.29
0.15% DNFB^b^ | 5 | 208.37 ± 5.25** | 10.02 ± 1.19**
5% ISO^b^ | 5 | 34.07 ± 5.25 | 1.64 ± 0.25

** Significantly different (p ≤ 0.01) from the vehicle control group by Shirley’s or Dunn’s test.

DPM = disintegrations per minute; stimulation index = ratio of treated group mean DPM/vehicle control group mean DPM; DNFB = 1-fluoro-2,4-dinitrobenzene; ISO = isoeugenol.

^a^ Data are presented as mean ± standard error.

^b^ Positive control.

Figure 2

^125^I-UdR Incorporation and Stimulation Index Data in the Dermal Hypersensitivity and Irritancy Study of 4-Methylcyclohexanemethanol

AOO = acetone/olive oil vehicle control; DNFB = 1-fluoro-2,4-dinitrobenzene positive control; DPM = disintegrations per minute; MCHM = 4-methylcyclohexanemethanol; SI = stimulation index; EC3 = concentration of test article that results in an SI = 3; N/A = not applicable; ** = significantly different (p ≤ 0.01) from the vehicle control group by Shirley’s or Dunn’s test; ## = significantly different (p ≤ 0.01) SI value from the vehicle control group by Shirley’s or Dunn’s test.

Two positive controls were utilized in the study of MCHM: 1-fluoro-2,4-dinitrobenzene (0.15%), a strong sensitizer, and isoeugenol (5%), a weak sensitizer. 1-Fluoro-2,4-dinitrobenzene performed as expected; however, isoeugenol did not elicit the anticipated sensitizing response.

## Crude 4-Methylcyclohexanemethanol

Crude MCHM was initially administered at concentrations of 1%, 2%, 5%, 20%, 40%, and 100%. All mice survived to the end of the study (Table 9 and Table 10). Clinical signs of toxicity, including eye squinting, hypoactivity, and isolation from cage mates, were observed on day 1 in mice in the 100% group (Table 11). Consequently, the concentration was lowered to 80% (this group is referred to hereafter as the 100/80% group) for exposure days 2 and 3. Clinical signs of toxicity in the 100/80% group included eye squinting (days 1 through 3), hypoactivity (days 1 and 2), and isolation from cage mates (days 1 and 2). All clinical signs of toxicity were observed during the afternoon observation period after treatment, but not during morning observation the subsequent day. No clinical signs of toxicity were observed in the groups administered 40% or less. Group mean body weights were not significantly affected by treatment (Table 10).

Table 9 Disposition of Female Mice in the Dermal Hypersensitivity and Irritancy Study of Crude 4-Methylcyclohexanemethanol

| Vehicle Control | 1% | 2% | 5% | 20% | 40% | 100/80% | 0.15% DNFB^a^ | 5% ISO^a^
Animals Initially in Study | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5
Terminal Removal | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5

DNFB = 1-fluoro-2,4-dinitrobenzene; ISO = isoeugenol.

^a^ Positive control.

Table 10 Survival and Mean Body Weights of Female Mice in the Dermal Hypersensitivity and Irritancy Study of Crude 4-Methylcyclohexanemethanol^a^

Concentration | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Absolute Weight Gain or Loss
Vehicle Control | 5/5 | 17.2 ± 0.6 | 17.9 ± 0.6 | 0.7 ± 0.2
1% | 5/5 | 17.1 ± 0.7 | 18.3 ± 0.7 | 1.2 ± 0.2
2% | 5/5 | 17.7 ± 0.8 | 18.3 ± 0.9 | 0.6 ± 0.2
5% | 5/5 | 17.4 ± 0.5 | 18.3 ± 0.5 | 0.9 ± 0.1
20% | 5/5 | 17.2 ± 0.6 | 18.2 ± 0.5 | 1.0 ± 0.2
40% | 5/5 | 18.2 ± 0.8 | 19.0 ± 0.8 | 0.9 ± 0.2
100/80% | 5/5 | 17.8 ± 0.7 | 17.6 ± 0.7 | −0.2 ± 0.1**
0.15% DNFB^c^ | 5/5 | 17.4 ± 0.6 | 18.3 ± 0.7 | 0.9 ± 0.3
5% ISO^c^ | 5/5 | 17.0 ± 0.4 | 17.5 ± 0.3 | 0.5 ± 0.2

** Significantly different (p ≤ 0.01) from the vehicle control group by Shirley’s or Dunn’s test.

DNFB = 1-fluoro-2,4-dinitrobenzene; ISO = isoeugenol.

^a^ Weights are given as mean ± standard error.

^b^ Number of animals surviving on day 6/number initially in group.

^c^ Positive control.

Table 11 Clinical Observations for Female Mice in the Dermal Hypersensitivity and Irritancy Study of Crude 4-Methylcyclohexanemethanol

| Vehicle Control | 1% | 2% | 5% | 20% | 40% | 100/80% | 0.15% DNFB^b^ | 5% ISO^c^
n | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5
Animal Behavior, Isolation^a^ | 0 | 0 | 0 | 0 | 0 | 0 | 5 (1) | 5 (1) | 0
Erythema, Ear, Bilateral, Mild | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 5 (4) | 0
Erythema, Ear, Bilateral, Moderate | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 5 (3) | 0
Eye Shut, Bilateral | 0 | 0 | 0 | 0 | 0 | 0 | 5 (1) | 5 (1) | 0
Hypoactivity | 0 | 0 | 0 | 0 | 0 | 0 | 5 (1) | 5 (3) | 0

DNFB = 1-fluoro-2,4-dinitrobenzene; ISO = isoeugenol.

^a^ Number of animals with observation (study day first observed).

^b^ Positive control.

^c^ Positive control (did not perform as expected).

Compared to that of the vehicle control group, mean ear thickness was significantly increased on day 6 (3.86%) in the 20% group (Table 12) only. There was a significant concentration-related trend for increased ear swelling on day 3.

Table 12 Summary of Ear Thickness Measurement Data for Female Mice in the Dermal Hypersensitivity and Irritancy Study of Crude 4-Methylcyclohexanemethanol^a^

Concentration | Day 1 (mm × 10^−2^) | Day 3 (mm × 10^−2^) | Day 6 (mm × 10^−2^) | Day 3 (%) | Day 6 (%) | Ear Weight (mg)
Vehicle Control | 15.58 ± 0.17 (5) | 15.66 ± 0.14^▲▲^ (5) | 15.56 ± 0.1^▲▲^ (5) | −0.04 ± 0.96^▲▲^ (5) | 0.02 ± 0.78^▲▲^ (5) | 7.78 ± 0.42 (5)
1% | 15.78 ± 0.08 (5) | 15.54 ± 0.07 (5) | 15.72 ± 0.10 (5) | −0.84 ± 0.39 (5) | 0.98 ± 0.60 (5) | 8.10 ± 0.52 (5)
2% | 15.52 ± 0.08 (5) | 15.50 ± 0.00 (5) | 15.50 ± 0.00 (5) | −1.00 ± 0.00 (5) | −0.30 ± 0.00 (5) | 8.42 ± 0.46 (5)
5% | 15.82 ± 0.09 (5) | 15.98 ± 0.09 (5) | 15.74 ± 0.09 (5) | 1.88 ± 0.60 (5) | 1.14 ± 0.53 (5) | 8.40 ± 1.14 (5)
20% | 15.22 ± 0.10 (5) | 16.56 ± 0.17 (5) | 16.16 ± 0.10** (5) | 5.72 ± 1.06 (5) | 3.86 ± 0.64** (5) | 8.98 ± 0.43 (5)
40% | 15.46 ± 0.16 (5) | 15.88 ± 0.05 (5) | 15.56 ± 0.06 (5) | 1.24 ± 0.39 (5) | 0.02 ± 0.32 (5) | 8.32 ± 0.12 (5)
100/80% | 15.42 ± 0.13 (5) | 16.14 ± 0.19 (5) | 15.72 ± 0.10 (5) | 3.00 ± 1.24 (5) | 0.98 ± 0.60 (5) | 8.66 ± 1.10 (5)
0.15% DNFB^b^ | 15.34 ± 0.04 (5) | 16.94 ± 0.13** (5) | 16.98 ± 0.09** (5) | 8.12 ± 0.78** (5) | 8.98 ± 0.60**(5) | 11.60 ± 0.79** (5)
5% ISO^b^ | 15.40 ± 0.10 (5) | 16.92 ± 0.05** (5) | 16.60 ± 0.19* (5) | 7.96 ± 0.39** (5) | 6.74 ± 1.20* (5) | 8.10 ± 1.02 (5)

^▲▲^Significant trend (p ≤ 0.01) by Jonckheere’s test.

* Significantly different (p ≤ 0.05) from the vehicle control group by Shirley’s or Dunn’s test.

** p ≤ 0.01.

DNFB = 1-fluoro-2,4-dinitrobenzene; ISO = isoeugenol.

^a^ Ear thickness data are presented as mean ± standard error (n); percentages are calculated as ear swelling (difference from vehicle control) using the equation: [mean measurement for both ears for each animal (day 3 or 6) − vehicle control mean ear thickness (day 3 or 6)]/[vehicle mean ear thickness (day 3 or 6) × 100].

^b^ Positive control.

In the 5% or greater groups, incorporation of ^125^I-UdR (expressed as mean DPM) into lymphocytes from the draining lymph nodes was significantly increased relative to vehicle controls, and this proliferative response followed a significant concentration-related trend. Mean DPM values ranged from 47.53 to 100.41 DPM in the 5% or greater groups (Table 13 and Figure 3). Mice treated with 5% or greater had significantly increased mean SI values, with SI values of more than 3.0 occurring at 40% (3.09) and 100/80% (4.83). The concentration that would result in an SI of 3.0 (EC3), was calculated to be 34.6% (Figure 3).

Table 13 Summary of ^125^I-UdR Incorporation and Stimulation Index for Female Mice in the Dermal Hypersensitivity and Irritancy Study of Crude 4-Methylcyclohexanemethanol^a^

Concentration | n | Lymph Node Counts (DPM) | Stimulation Index
Vehicle Control | 5 | 20.76 ± 4.67^▲▲^ | 1.00 ± 0.22^▲▲^
1% | 5 | 38.16 ± 13.29 | 1.83 ± 0.64
2% | 5 | 35.96 ± 3.05 | 1.73 ± 0.15
5% | 5 | 47.53 ± 5.68* | 2.29 ± 0.27*
20% | 5 | 61.35 ± 6.82** | 2.95 ± 0.33**
40% | 5 | 64.32 ± 12.07** | 3.09 ± 0.58**
100/80% | 5 | 100.41 ± 16.89** | 4.83 ± 0.81**
0.15% DNFB^b^ | 5 | 208.37 ± 5.25** | 10.02 ± 1.19**
5% ISO^b^ | 5 | 34.07 ± 5.25 | 1.64 ± 0.25

^▲▲^Significant trend (p ≤ 0.01) by Jonckheere’s test.

* Significantly different (p ≤ 0.05) from the vehicle control group by Shirley’s or Dunn’s test.

** p ≤ 0.01.

DPM = disintegrations per minute; stimulation index = ratio of treated group mean DPM/vehicle control group mean DPM; DNFB = 1-fluoro-2,4-dinitrobenzene; ISO = isoeugenol.

^a^ Data are presented as mean ± standard error.

^b^ Positive control.

Figure 3

^125^I-UdR Incorporation and Stimulation Index Data in the Dermal Hypersensitivity and Irritancy Study of Crude 4-Methylcyclohexanemethanol

AOO = acetone/olive oil vehicle control; DNFB = 1-fluoro-2,4-dinitrobenzene positive control; DPM = disintegrations per minute; MCHM = 4-methylcyclohexanemethanol; SI = stimulation index; EC3 = concentration of test article that results in an SI 3; ΔΔ = significant trend (p ≤ 0.01) for DPM by Jonckheere’s test; * = significantly different (p ≤ 0.05) from the vehicle control group by Shirley’s or Dunn’s test; ** = (p ≤ 0.01); # = significantly different (p ≤ 0.05) SI value from the vehicle control group by Shirley’s or Dunn’s test; ## = (p ≤ 0.01).

The positive controls utilized for the study of crude MCHM, 1-fluoro-2,4-dinitrobenzene (0.15%), and isoeugenol (5%) were shared controls with the study of MCHM. 1-Fluoro-2,4-dinitrobenzene performed as expected; however, isoeugenol did not elicit the anticipated sensitizing response.

## Crude 4-Methylcyclohexanemethanol (Repeat Study)

A repeat study of crude MCHM was conducted to confirm the results observed in the initial study and more clearly establish levels at which the test article induced sensitization in the absence of clinical toxicity. Crude MCHM was administered at concentrations of 1%, 5%, 25%, 50%, and 75%. All mice survived to the end of the study (Table 14 and Table 15). Clinical signs of toxicity were observed on days 1 through 3 in the 75% group and included eye squinting (in 8 of 13 mice) and isolation from cage mates (all 13 mice); isolation from cage mates was also observed on day 1 in all 13 mice in the 50% group (Table 16). All clinical signs of toxicity were observed during the afternoon after treatment, and none was observed during morning observation the subsequent day. No clinical signs of toxicity were observed in the 1%, 5%, or 25% groups. Group mean body weights were not significantly affected by treatment (Table 15).

Table 14 Disposition of Female Mice in the Dermal Hypersensitivity and Irritancy Study of Crude 4-Methylcyclohexanemethanol (Repeat Study)

| Vehicle Control | 1% | 5% | 25% | 50% | 75% | 0.15% DNFB^a^
Animals Initially in Study | 13 | 13 | 13 | 13 | 13 | 13 | 13
Terminal Removal | 13 | 13 | 13 | 13 | 13 | 13 | 13

DNFB = 1-fluoro-2,4-dinitrobenzene.

^a^ Positive control.

Table 15 Survival and Mean Body Weights of Female Mice in the Dermal Hypersensitivity and Irritancy Study of Crude 4-Methylcyclohexanemethanol (Repeat Study)^a^

Concentration | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Absolute Weight Gain or Loss
Vehicle Control | 13/13 | 16.9 ± 0.3 | 17.2 ± 0.2 | 0.2 ± 0.1^▲▲^
1% | 13/13 | 17.2 ± 0.4 | 17.3 ± 0.3 | 0.1 ± 0.1
5% | 13/13 | 17.3 ± 0.3 | 17.8 ± 0.3 | 0.5 ± 0.1
25% | 13/13 | 17.2 ± 0.3 | 17.5 ± 0.3 | 0.3 ± 0.1
50% | 13/13 | 17.3 ± 2.0 | 17.7 ± 0.3 | 0.4 ± 0.1
75% | 13/13 | 17.1 ± 1.0 | 17.6 ± 0.3 | 0.5 ± 0.1
0.15% DNFB^c^ | 13/13 | 17.4 ± 0.3 | 17.7 ± 0.3 | 0.3 ± 0.1

^▲▲^Significant trend (p ≤ 0.01) by Jonckheere’s test.

^a^ Weights are given as mean ± standard error.

^b^ Number of animals surviving on day 6/number initially in group.

^c^ Positive control; DNFB = 1-fluoro-2,4-dinitrobenzene.

Table 16 Clinical Observations for Female Mice in the Dermal Hypersensitivity and Irritancy Study of Crude 4-Methylcyclohexanemethanol (Repeat Study)

| Vehicle Control | 1% | 5% | 25% | 50% | 75% | 0.15% DNFB^b^
n | 13 | 13 | 13 | 13 | 13 | 13 | 13
Animal Behavior, Isolation^a^ | 0 | 0 | 0 | 0 | 13 (1) | 13 (1) | 13 (1)
Erythema, Ear, Bilateral, Mild | 0 | 0 | 0 | 0 | 0 | 0 | 13 (5)
Eye Shut, Bilateral | 0 | 0 | 0 | 0 | 0 | 8 (1) | 4 (1)

DNFB = 1-fluoro-2,4-dinitrobenzene.

^a^ Number of animals with observation (study day first observed).

^b^ Positive control.

Ear thickness in the 75% group was significantly increased relative to that of the vehicle control group on days 3 (1.63%) and 6 (2.39%) (Table 17). Ear swelling was also increased in the 100/80% group in the initial study of crude MCHM, however, not to a significant extent (Table 12). No changes in ear thickness were observed in the remaining dosed groups (Table 17).

Table 17 Summary of Ear Thickness Measurement Data for Female Mice in the Dermal Hypersensitivity and Irritancy Study of Crude 4-Methylcyclohexanemethanol (Repeat Study)^a^

Concentration | Day 1 (mm × 10^−2^) | Day 3 (mm × 10^−2^) | Day 6 (mm × 10^−2^) | Day 3 (%) | Day 6 (%) | Ear Weight (mg)
Vehicle Control | 18.01 ± 0.03^▲▲^ (13) | 17.92 ± 0.04^▲▲^ (13) | 17.56 ± 0.04^▲▲^ (13) | 0.02 ± 0.24^▲▲^ (13) | 0.02 ± 0.23^▲▲^ (13) | 8.62 ± 0.10 (5)
1% | 17.66 ± 0.07** (13) | 17.88 ± 0.06 (13) | 17.50 ± 0.01 (13) | −0.20 ± 0.31 (13) | −0.31 ± 0.09 (13) | 8.08 ± 0.42 (5)
5% | 17.52 ± 0.06** (13) | 17.82 ± 0.06 (13) | 17.60 ± 0.05 (13) | −0.52 ± 0.36 (13) | 0.24 ± 0.26 (13) | 8.9 ± 0.58 (5)
25% | 17.55 ± 0.06** (13) | 17.89 ± 0.05 (13) | 17.58 ± 0.04 (13) | −0.15 ± 0.30 (13) | 0.13 ± 0.23 (13) | 9.28 ± 0.35 (5)
50% | 17.47 ± 0.05** (13) | 17.96 ± 0.06 (13) | 17.65 ± 0.08 (13) | 0.28 ± 0.03 (13) | 0.52 ± 0.47 (13) | 9.60 ± 0.63 (5)
75% | 17.40 ± 0.04** (13) | 18.21 ± 0.06** (13) | 17.99 ± 0.06** (13) | 1.63 ± 0.30** (13) | 2.39 ± 0.33** (13) | 8.96 ± 0.52 (5)
0.15% DNFB^b^ | 17.35 ± 0.06** (13) | 18.00 ± 0.02 (13) | 18.77 ± 0.14** (13) | 0.50 ± 0.14 (13) | 6.77 ± 0.79**(13) | 11.88 ± 0.66** (5)

^▲▲^Significant trend (p ≤ 0.01) by Jonckheere’s test.

** Significantly different (p ≤ 0.01) from the vehicle control group by Shirley’s or Dunn’s test.

DNFB = 1-fluoro-2,4-dinitrobenzene.

^a^ Ear thickness data are presented as mean ± standard error (n); percentages are calculated as ear swelling (difference from vehicle control) using the equation: [mean measurement for both ears for each animal (day 3 or 6) − vehicle control mean ear thickness (day 3 or 6)]/[vehicle control mean ear thickness (day 3 or 6) × 100].

^b^ Positive control.

Generally, concentration-related increases in DPM values occurred, and the increases were significant at 50% (68.29 DPM) and 75% (128.43 DPM) (Table 18 and Figure 4). Increased DPM values correlated with concentration-related increases in SI values that were also significant in the 50% (2.24) and 75% (4.22) groups. The increase in DPM in the 50% group occurred in the absence of irritation, suggesting that crude MCHM is a sensitizer. The positive control, DNFB (0.15%), performed as expected. The concentration that would result in an SI of 3.0 (EC3) was calculated to be 60.0% (Figure 4).

Table 18 Summary of ^125^I-Udr Incorporation and Stimulation Index Data for Female Mice in the Dermal Hypersensitivity and Irritancy Study of Crude 4-Methylcyclohexanemethanol (Repeat Study)^a^

Concentration | n | Lymph Node Counts (DPM) | Stimulation Index
Vehicle Control | 8 | 30.46 ± 7.28^▲▲^ | 1.00 ± 0.24^▲▲^
1% | 8 | 33.42 ± 8.63 | 1.10 ± 0.28
5% | 8 | 22.25 ± 2.98 | 0.73 ± 0.10
25% | 8 | 44.14 ± 8.23 | 1.45 ± 0.27
50% | 8 | 68.29 ± 14.10* | 2.24 ± 0.46*
75% | 8 | 128.43 ± 16.45** | 4.22 ± 0.54**
0.15% DNFB^b^ | 8 | 2,315.52 ± 380.62** | 76.02 ± 12.50**

^▲▲^Significant trend (p ≤ 0.01) by Jonckheere’s test.

* Significantly different (p ≤ 0.05) from the vehicle control group by Shirley’s or Dunn’s test.

** p ≤ 0.01.

DNFB = 1-fluoro-2,4-dinitrobenzene.

^a^ Data are presented as mean ± standard error; DPM = disintegrations per minute; stimulation index = ratio of treated group mean DPM/vehicle control group mean DPM.

^b^ Positive control.

Figure 4

^125^I-UdR Incorporation and Stimulation Index Data in the Dermal Hypersensitivity and Irritancy Study of Crude 4-Methylcyclohexanemethanol (Repeat Study)

AOO = acetone/olive oil vehicle control; DNFB = 1-fluoro-2,4-dinitrobenzene positive control; DPM = disintegrations per minute; MCHM = 4-methylcyclohexanemethanol; SI = stimulation index; EC3 = concentration of test article that results in an SI = 3; ΔΔ = significant trend (p ≤ 0.01) for DPM by Jonckheere’s test; * = significantly different (p ≤ 0.05) from the vehicle control group by Shirley’s or Dunn’s test; ** = (p ≤ 0.01); # = significantly different (p ≤ 0.05) SI value from the vehicle control group by Shirley’s or Dunn’s test; ## = (p ≤ 0.01).