# Materials and Methods

## Procurement and Characterization

### 4-Methylcyclohexanemethanol

4-Methylcyclohexanemethanol (MCHM) was obtained from TCI America (Portland, OR) in one lot (KDY3F). Crude MCHM was obtained from Eastman Chemical Company (Kingsport, TN) in one lot (TP14044373). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at MRIGlobal (Kansas City, MO) (Appendix A). Reports on analyses performed in support of the MCHM studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Lot KDY3F of the pure chemical, a clear, colorless liquid, was identified as MCHM using Fourier transform infrared (FTIR) spectroscopy, Fourier transform proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy, and gas chromatography (GC) with mass spectrometry (MS) detection. In addition, boiling point, density, and octanol:water partition coefficient were determined. Karl Fischer titration was used to determine the water content of lot KDY3F. Purity of the test article was determined by elemental analyses for carbon, hydrogen, and nitrogen, and by determining the purity profile using GC with flame ionization detection (FID) and two columns with differing polarities.

For lot KDY3F, Karl Fischer titration indicated 0.21% water. Elemental analyses for carbon, hydrogen, and nitrogen were consistent with the theoretical values for MCHM. GC/FID analysis detected two major peaks with a combined area of 99.97% of the total peak area and no impurities with areas greater than or equal to 0.05% of the total peak area. The relative areas of the two major peaks indicated that MCHM consisted of 67.99% cis- and 31.98% trans-isomers. GC/FID by a second system detected two major peaks with a combined relative area of 99.83% (with relative areas of 67.80% [cis] and 32.03% [trans] isomers), and two minor impurities totaling 0.13% of the total peak area. The overall purity of lot KDY3F was determined to be greater than or equal to 99.8%.

A chemical identity and purity screen of lot TP14044373 of the crude test chemical, a clear liquid, was performed using GC/MS. The test article was found to be a 90.35% mix of the cis-(33.45%) and trans- (56.90%) isomers of MCHM on the basis of the relative areas of the two major peaks (Table 1). Six impurity components with a relative percent total area greater than or equal to 0.05% were observed, with a combined area of 9.66%. Three of these impurity components (each with an individual relative percent area greater than 1%) were tentatively identified as cyclohexanemethanol (1.82%), and a mix of the cis- and trans- isomers of 1,4-cyclohexanedimethanol (7.15%). The purity of lot TP14044373, relative to MCHM isomers, was estimated to be greater than 90%.

Table 1 Constituents of Crude 4-Methylcyclohexanemethanol

Chemical Name | CASRN | Concentration (%)
4-Methylcyclohexanemethanol | 34885-03-5 | 90.35
Trans-isomer | – | 56.90
Cis-isomer | – | 33.45
Other Components Tentatively Identified | – | 10.0 (approximately)
1,4-Cyclohexanedimethanol (cis- and trans- isomers) | 105-08-8 | 7.15
Cyclohexanemethanol | 100-49-2 | 1.82
Methyl 4-methylcyclohexanecarboxylate | 51181-40-9 | 0.50
Cis-octahydroisobenzofuran | 13149-01-4 | 0.13
2-Ethyl-1-hexanol | 104-76-7 | 0.06

Stability studies of lot KDY3F were conducted using GC/FID. These studies indicated that MCHM was stable as a bulk chemical for at least 14 days when stored in amber glass vials under an inert headspace at temperatures up to 60°C. To ensure stability, both bulk chemicals were stored at room temperature in amber glass bottles, and MCHM was stored under an inert headspace.

### Isoeugenol

Isoeugenol was obtained from Sigma-Aldrich, Inc. (St. Louis, MO) in one lot (05622BEV) that was used as a positive control in the initial dermal hypersensitivity and irritancy study. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Research Triangle Institute (RTI) (Research Triangle Park, NC).

The identity of lot 05622BEV, received as a clear liquid, was determined using FTIR and proton and carbon-13 NMR spectroscopy, GC/MS spectrometry, and ultra-high-performance liquid chromatography (UHPLC)/time-of-flight (TOF) MS. Karl Fischer titration was used to determine the water content of lot 05622BEV. Purity of the test article was determined by elemental analyses for carbon, hydrogen, and oxygen, and by determining the purity profile using GC/FID and UHPLC with photodiode array (PDA) detection.

For lot 05622BEV, Karl Fischer titration indicated 0.23% water. Elemental analyses for carbon, hydrogen, and oxygen were in agreement with the theoretical values for isoeugenol. GC/FID analysis indicated two major isomer peaks (totaling 98.7% of the total peak area) and two impurities (0.7% and 0.4% of the total peak area). UHPLC/PDA analysis indicated two major isomer peaks (totaling 99.1% of the total peak area) and two impurities (0.6% and 0.1% of the total peak area). The overall purity of lot 05622BEV was determined to be greater than or equal to 98.7%.

Stability studies of lot 05622BEV conducted using GC/FID indicated that isoeugenol was stable as a bulk chemical for at least 14 days when stored in amber glass vials sealed with Teflon^®^-lined caps at temperatures up to 60°C. To ensure stability, the bulk chemical was stored at room temperature under nitrogen.

### 1-Fluoro-2,4-dinitrobenzene

1-Fluoro-2,4-dinitrobenzene was obtained from Sigma-Aldrich, Inc. in one lot (BCBN2339V) that was used as a positive control in the initial and repeat dermal hypersensitivity and irritancy studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at RTI.

The identity of lot BCBN2339V, a clear liquid, was determined using FTIR and proton, carbon-13, and fluorine-19 NMR spectroscopy, GC/MS spectrometry, and UHPLC/TOF MS. The water content of lot BCBN2339V was determined using Karl Fischer titration. Purity of the test article was determined by elemental analyses for carbon, hydrogen, nitrogen, oxygen, and fluorine, and by determining the purity profile using GC/FID and UHPLC with PDA detection.

For lot BCBN2339V, the water content was less than the limit of quantitation of 0.1%. Elemental analyses for carbon, hydrogen, nitrogen, and oxygen were in agreement with the theoretical values for 1-fluoro-2,4-dinitrobenzene; fluorine was not accurately quantitated due to interference with oxygen. GC/FID indicated one major peak (99.6% of the total peak area), and two impurity peaks (0.2% each of the total peak area). UHPLC/PDA analysis indicated one major peak (99.4% of the total peak area) and three impurity peaks (0.1%, 0.2%, and 0.3% of the total peak area). The overall purity of lot BCBN2339V was determined to be greater than or equal to 99.4%.

Stability studies of lot BCBN2339V conducted using GC/FID indicated that 1-fluoro-2,4-dinitrobenzene was stable as a bulk chemical for at least 14 days when stored in amber glass vials sealed with Teflon-lined caps at temperatures up to 60°C. To ensure stability, the bulk chemical was stored at room temperature under nitrogen.

## Preparation and Analysis of Dose Formulations

### Formulation Materials

For the initial study, all dose formulations were prepared by the study laboratory, Burleson Research Technologies, Inc. (Morrisville, NC), and analyzed by the analytical chemistry laboratory at RTI. For the repeat study, formulations were both prepared and analyzed by RTI.

Acetone and olive oil were obtained from multiple suppliers in multiple lots and these materials were combined with a 4:1 ratio to prepare the vehicle for the initial and repeat studies. For the repeat study, J.T. Baker Acetone (lot K30J01; Thermofisher Scientific, Waltham, MA) was analyzed using GC/FID indicating a purity of 99.9%, acceptable for use in the study. Olive oil (lot 0240-0545; Welch, Holme, and Clark Co., Newark, NJ) was analyzed to determine peroxide levels using potentiometric titration. Peroxide levels were within the acceptable limit of 5 mEq/kg.

Dose formulations of the test articles and positive controls for the initial study were prepared daily by mixing the appropriate amounts of each chemical with acetone:olive oil (4:1) to achieve the required concentrations. In the repeat study the dose formulations were stored in amber glass vials sealed with Teflon-lined caps at room temperature or refrigerated temperatures for up to 14 days.

Stability studies of the 1% (v/v) dose formulation of crude MCHM and the 0.15% (v/v) dose formulation of 1-fluoro-2,4-dinitrobenzene were performed by RTI using two different GC/FID systems. Stability was confirmed for at least 14 days for these dose formulations stored in amber glass vials with minimal headspace sealed with Teflon-lined lids at room temperature and for 3 hours under simulated animal room conditions.

Analyses of the dose formulations for the initial and repeat studies were conducted by RTI using GC/FID by one system for MCHM and crude MCHM and by a second system for the positive controls isoeugenol and 1-fluoro-2,4-dinitrobenzene. During the initial dermal hypersensitivity and irritancy study, the dose formulations were analyzed once; two of three MCHM dose formulations were within 15% of the target concentrations and five of six crude MCHM dose formulations were within 15% of the target concentrations (Table A-3). Single dose formulations of the positive controls isoeugenol and 1-fluoro-2,4-dinitrobenzene were each found to be within 15% of the target concentrations. During the repeat dermal hypersensitivity and irritancy study, the dose formulations were analyzed once, and animal room samples of these dose formulations were also analyzed (Table A-4). All five crude MCHM dose formulations were within 15% of the target concentrations; all five animal room samples were also within 15% of the target concentrations. A single dose formulation of 1-fluoro-2,4-dinitrobenzene and its associated animal room sample were both found to be within 15% of the target concentrations.

## Animal Source

Female BALB/c mice were obtained from Taconic Biosciences, Inc. (Germantown, NY). The National Toxicology Program (NTP) notes that the CBA mouse is the strain of choice for the local lymph node assay (LLNA). NTP began using BALB/c mice for hypersensitivity testing prior to the development of the OECD 429 Guidance. To maintain consistency with a large body of historical data, NTP continues to use the BALB/c mouse. NTP and others have conducted studies to examine the sensitivity of this mouse strain as compared with the CBA and multiple groups have concluded that the performance of LLNA with BALB/c mice is comparable with that of the CBA mouse.^29-31^

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the Burleson Research Technologies, Inc., Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Dermal Hypersensitivity and Irritancy Studies

### Study Conduct

Female mice were 5 to 7 weeks old upon receipt. Animals were quarantined for 8 (initial MCHM and crude MCHM study) or 17 (crude MCHM repeat study) days and were 8 weeks old on the first day of dosing. Before the studies began, five mice were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

In the initial study evaluating whether MCHM and crude MCHM have similar immunotoxicologic profiles, groups of five mice were administered a vehicle control (acetone/olive oil, 4:1 v/v [AOO]); one of two positive controls (1-fluoro-2,4-dinitrobenzene [0.15% in AOO] or isoeugenol [5% in AOO]); 2%, 20%, or 100/50% formulations of MCHM in AOO; or 1%, 2%, 5%, 20%, 40%, or 100/80% formulations of crude MCHM in AOO. The 100/50% group was administered 100% on day 1 and 50% on days 2 and 3; the 100/80% group was administered 100% on day 1 and 80% on days 2 and 3. Doses of MCHM and crude MCHM were selected on the basis of dermal immunotoxicity studies previously performed by the sponsor, Eastman Kodak Company.^18,25,26^ To determine if the crude mixture of MCHM was responsible for any potential dermal immunotoxicity, three concentrations (2%, 20%, and 100%) were chosen for comparison between MCHM and crude MCHM.

A repeat study of crude MCHM was undertaken to more clearly establish levels in which the test article induced sensitization in the absence of clinical toxicity. In the repeat study of crude MCHM, groups of eight (groups 1 through 7) or five (groups 8 through 14) female mice were administered the AOO vehicle control; a positive control (1-fluoro-2,4-dinitrobenzene [0.15% in AOO]); or crude MCHM at concentrations of 1%, 5%, 25%, 50%, or 75% in AOO (Table 2).

Table 2 Study Design for the Repeat Study of Crude 4-Methylcyclohexanemethanol

| Group^a,b^
| 1 | 2 | 3 | 4 | 5 | 6 | 7 | 8 | 9 | 10 | 11 | 12 | 13 | 14
Treatment | AOO | 1% | 5% | 25% | 50% | 75% | DNFB | AOO | 1% | 5% | 25% | 50% | 75% | DNFB
Endpoint
Body Weight | x | x | x | x | x | x | x | x | x | x | x | x | x | x
Clinical Observations | x | x | x | x | x | x | x | x | x | x | x | x | x | x
Ear Thickness | x | x | x | x | x | x | x | x | x | x | x | x | x | x
Lymph Node Cell Proliferation | x | x | x | x | x | x | x | – | – | – | – | – | – | –
Ear Punch Biopsy Weight | – | – | – | – | – | – | – | x | x | x | x | x | x | x
Ear Histopathology | – | – | – | – | – | – | – | x | x | x | x | x | x | x

X indicates groups for which the endpoint listed was assessed.

AOO = acetone olive oil; DNFB = 1-fluoro-2,4-dinitrobenzene.

^a^ Groups 1 through 7 received ^125^I-UdrR on day 6 for evaluation of lymph node cell proliferation. Ear punch biopsy weights were obtained only for groups 8 through 14 following euthanasia on day 6.

^b^ n = 8 for groups 1–7; n = 5 for groups 8–14.

The mice were treated for 3 consecutive days by direct epicutaneous application of 25 µL of the test or control article to the dorsum of each ear. Feed and water were available ad libitum. The animals were housed up to five mice from the same treatment group per cage. Animals were weighed on days 1 and 6. Mice were observed twice daily for local irritation at the application site and for signs of systemic toxicity. Details of the study design and animal maintenance are summarized in Table 3. Information on feed composition and contaminants is provided in Appendix B.

Table 3 Experimental Design and Materials and Methods in the Dermal Hypersensitivity and Irritancy Studies of 4-Methylcyclohexanemethanol and Crude 4-Methylcyclohexanemethanol

Study Design
Study Laboratory
Burleson Research Technologies, Inc. (Morrisville, NC)
Strain and Species
BALB/c mice
Animal Source
Taconic Biosciences, Inc. (Germantown, NY)
Time Held Before Studies
MCHM and crude 4-methylcyclohexanemethanol: 8 days Crude MCHM (repeat study): 17 days
Average Age When Studies Began
8 weeks
Date of First Dose
MCHM and crude 4-methylcyclohexanemethanol: December 10, 2014 Crude MCHM (repeat study): March 20, 2015
Duration of Dosing
Once daily for 3 days
Date of Last Dose
MCHM and crude 4-methylcyclohexanemethanol: December 12, 2014 Crude MCHM (repeat study): March 22, 2015
Terminal Euthanasia
MCHM and crude 4-methylcyclohexanemethanol: December 15, 2014 Crude MCHM (repeat study): March 25, 2015
Average Age at Terminal Euthanasia
9 weeks
Size of Study Groups
MCHM and crude 4-methylcyclohexanemethanol: 5 Crude MCHM (repeat study): 8 (groups 1 through 7) or 5 (groups 8 through 14)
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage
5
Method of Animal Identification
Tail tattoo
Diet
Irradiated NTP-2000 open formula pelleted diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum
Water
Tap water (Morrisville municipal supply) (Techniplast caging system, Techniplast, West Chester, PA), available ad libitum
Cages
Techniplast Sealsafe, individually ventilated caging system (Techniplast)
Bedding
Sani-Chips^®^ (P.J. Murphy Forest Products Corp., Montville, NJ), changed twice weekly
Animal Room Environment
Temperature: 72°F ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: 10/hour
Concentrations
MCHM and crude MCHM: 0%, 2%, 20%, or 100/50% formulations of MCHM; 1%, 2%, 5%, 20%, 40%, or 100/80% formulations of crude MCHM; 0.15% 1-fluoro-2,4-dinitrobenzene or 5% isoeugenol Crude MCHM (repeat study): 1%, 5%, 25%, 50%, or 75% crude MCHM; or 0.15% 1-fluoro-2,4-dinitrobenzene Acetone:olive oil vehicle (AOO, 4:1 ratio) was used for all studies
Type and Frequency of Observation
Observed twice daily for toxicity and skin irritation at the application site; animals were weighed on days 1 and 6.
Method of Euthanasia
Carbon dioxide asphyxiation
Ear Thickness Measurements
Ear thickness measurements were taken for both ears of all mice on days 1, 3, and 6. On day 6, 6 mm punch biopsies were taken from each ear of MCHM and crude MCHM groups and crude MCHM (repeat study) groups 8 through 14 and weighed.
Local Lymph Node Assay
On day 6, 5 hours before terminal euthanasia, ^125^I-UdR (2 µCi) was administered by intravenous injection into the lateral tail vein of MCHM and crude MCHM groups and crude MCHM (repeat study) groups 1 through 7. After terminal kill, auricular lymph nodes were collected and disintegrations per minute and stimulation indices were determined.

### Assessment of Irritancy

Dermal irritancy potential was assessed by measuring changes in ear swelling following application of MCHM, crude MCHM, or vehicle controls. For all mice, ear thickness measurements for both ears were taken prior to dosing on day 1, after dosing on day 3, and again on day 6. Ear thickness measurements were performed using a calibrated gage (Dyer model 304-196; S/N 4183012). The thickness gage and the gage block were calibrated against NIST-traceable thickness standards by an independent certification laboratory that is ISO/IEC 17025-accredited. The precision of the calibrated gage allowed for ear thickness to be measured to 0.1 mm. Mice were euthanized by carbon dioxide asphyxiation on day 6. A 6 mm punch biopsy was obtained from each ear of mice in the initial MCHM and crude MCHM groups in the repeat study of crude MCHM (groups 8 through 14) following terminal euthanasia. The biopsies were weighed; however, technical limitations prevented the measurement of usable data.

### Assessment of Hypersensitivity

Dermal hypersensitivity was evaluated using the LLNA, which provides an indication for the skin sensitization potential of a chemical.^32-34^ In the assay, skin sensitization potential was measured as a function of lymphocyte proliferation within the auricular lymph nodes following dermal application of MCHM, crude MCHM, or vehicle controls to both ears.

On day 6, after ear thickness measurements and 5 hours before terminal euthanasia, mice in the initial study of MCHM and crude MCHM groups 1 through 7 were administered 2 µCi ^125^I-iododeoxyuridine (^125^I-UdR) (0.25 mL of a stock solution of 8 µCi/mL) by intravenous injection into the lateral tail vein using a tuberculin syringe. The auricular lymph nodes were collected after terminal euthanasia into a 15 mL conical tube containing Hanks’ balanced salt solution with HEPES (HBSS/H). The lymph nodes collected from an individual animal were pooled in a single tube. The lymph nodes were placed between the frosted ends of two glass microscope slides and macerated to produce a cell suspension. The cell suspensions were placed into centrifuge tubes containing HBSS/H and processed through centrifugations and washes. Trichloroacetic acid (TCA, 5%) was added to the tubes containing the final centrifugation pellet. The tubes were vortexed and then wrapped in lead foil and refrigerated overnight (16 to 24 hours). Subsequently, the tubes were removed from refrigeration, vortexed, and centrifuged. The resulting pellets were resuspended with 5% TCA and added to a gamma counter tube (1 gamma counter tube per mouse). Each tube was counted on the gamma counter for 5 minutes and counts per minute (CPM) were recorded. A 1:500 dilution of the 8 µCi/mL ^125^I-UdR stock solution was prepared and counted. Four background/blank tubes, each containing 2 mL of 5% TCA were also counted. CPM values were converted to disintegrations per minute (DPM) by dividing by the gamma counter efficiency and multiplying the results by 100. Individual DPM values were corrected by subtracting the mean DPM for the blanks. The stimulation index (SI) was calculated by dividing the group mean DPM by the mean vehicle control DPM. SI is the accepted standard for quantification of skin sensitization potential, and an SI of 3 (a threefold increase in lymphocyte proliferation) has previously been determined to be a consistent distinguishing factor between sensitizers and nonsensitizers.^35^ The EC3 value, or effective concentration for an SI of 3, has further been successfully used to directly determine the skin sensitization potential of chemicals.^34^ The EC3 values were calculated via a linear regression model; all of the study data were used for the linear interpolation.

## Statistical Methods

All p values are two-sided and considered statistically significant if less than 0.05.

### Analysis of Continuous Variables

For dosed groups compared to the vehicle control groups, two approaches were employed to assess the significance of pairwise comparisons in the analysis of continuous variables. Body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^36^ and Williams.^37,38^ Ear thickness, lymph node counts, and stimulation indices, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^39^ (as modified by Williams^40^) and Dunn.^41^ Jonckheere’s test^42^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than would be a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^43^ were examined by NTP personnel, and implausible values were eliminated from the analysis.

## Quality Assurance Methods

The dermal hypersensitivity and irritancy studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^44^ In addition, as records from the studies were submitted to the NTP Archives, they were audited retrospectively by an independent quality assessment contractor. Separate audits covered both completeness and accuracy of the data and a draft of this NTP Immunotoxicity Study Report. Audit procedures and findings are presented in the audit report and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Immunotoxicity Study Report.