# Introduction

Figure 1

MCHM (CASRN 34885-03-5; Chemical Formula: C_8_H_16_O; Molecular Weight: 128.21) and Crude MCHM (CASRN N/A)

Synonyms: Cyclohexanemethanol, 4-methyl-; 4-methyl-1-cyclohexanemethanol; (4-methylcyclohexyl)methanol.

## Chemical and Physical Properties

4-Methylcyclohexanemethanol (MCHM) is an organic compound with a molecular weight of 128.21 g/mol and a density of 0.9074 g/cm^3^. MCHM has estimated boiling and melting points of 203.7°C and −12.0°C, respectively, and a vapor pressure of 0.0588 mm Hg at 25°C. It has an estimated water solubility of 2.024 × 10^3^ mg/L (at 25°C) and an estimated log K_OW_ of 2.55. MCHM is a clear, colorless oil and has been reported to have an alcohol or licorice-like odor.^1-3^ MCHM exists as two distinct isomers, cis-MCHM and trans-MCHM; the trans-isomer, believed to be the source of the licorice odor, has an air odor threshold concentration of 0.060 ppb/v.^4,5^

MCHM is commonly sold as a crude mixture, which can contain 68% to 89% MCHM with additional components including 4-(methoxymethyl)cyclohexanemethanol (CASRN 98955-27-2;4% to 22%), water (4% to 10%), methyl 4-methylcyclohexanecarboxylate (CASRN 51181-40-9; 5%), dimethyl 1,4-cyclohexanedicarboxylate (CASRN 94-60-0; 1%), 1,4-cyclohexanedimethanol (CASRN 105-08-8; 1% to 2%), and methanol (1%).^3^ Crude MCHM has a boiling point of 180°C, a freezing point of 0°C, and a vapor pressure of 18.0 mm Hg at 20°C.^3^

4-(Methoxymethyl)cyclohexanemethanol has a molecular weight of 158.24 g/mol, and methyl 4-methylcyclohexanecarboxylate has a molecular weight of 156.22 g/mol.^6,7^ No information is available on additional chemical or physical properties of 4-(methoxymethyl)cyclohexanemethanol or methyl 4-methylcyclohexanecarboxylate.

Dimethyl 1,4-cyclohexanedicarboxylate is a partially crystalized liquid with a molecular weight of 200.23 g/mol, a boiling point of 259°C (at 760 mm Hg), and a melting point of either 14°C (cis-isomer) or 71°C (trans-isomer). The vapor pressure of dimethyl 1,4-cyclohexanedicarboxylate is 1 mm Hg at 85.1°C.^8^

1,4-Cyclohexanedimethanol is a white, waxy solid with a molecular weight of 144.21 g/mol and a density of 1,023 g/L (at 50°C). It has a melting point range of 41°C to 61°C, a boiling point range of 284°C to 285°C, and a freezing point of 24°C.^9^

## Production, Use, and Human Exposure

Information regarding the production volume of MCHM is currently unavailable. MCHM is used as a flotation reagent in fine coal beneficiation. Human exposure can occur during handling or use of the chemical.

On January 9, 2014, approximately 10,000 gallons of a mixture of chemicals containing predominantly MCHM was leaked into the Elk River upstream of the intake for West Virginia American Water Company’s Elk River plant, a municipal water source serving approximately 300,000 people in Charleston, West Virginia.^10^ A number of chemicals were identified in the spill, including crude MCHM (estimated at 88.5%), propylene glycol ether, and dipropylene glycol phenyl ether.^11^ Of the crude MCHM in the mixture, MCHM alone was estimated to be 75% of the entire 10,000-gallon spill.^12^ This spill temporarily contaminated 15% of the state’s tap water, and prior to flushing water lines, concentrations of MCHM in tap water ranged from less than 10 ppb up to 420 ppb; levels of the other components of crude MCHM were not measured.^13^ Concentrations of MCHM were also measured at the intake (up to 3.35 ppm) and posttreatment (up to 2.4 ppm).^10^ Exposure to 2.4 ppm is approximately equivalent to 0.07 mg/kg body weight per day for an adult (70 kg) consuming 2 L of water a day and 0.24 mg/kg per day for a child (10 kg) consuming 1 L of water a day. Levels of the other components of crude MCHM were not measured.

## Regulatory Status

Workplace exposure limits for MCHM are currently unavailable. Immediately following the Elk River spill, the Center for Disease Control and Prevention (CDC) and the Agency for Toxic Substances and Disease Registry (ATSDR) established a short-term drinking water limit of 1 ppm based on the approximate weight (10 kg) and drinking water intake (1 L) of a child.^12^ Evaluation of the same data using differing adjustment factors resulted in a calculated health advisory level of 120 ppb.^14^

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

There are no studies in the literature on the absorption, distribution, metabolism, or excretion of MCHM in experimental animals.

Radiolabeled [^14^C] 1,4-cyclohexanedimethanol (70% trans, 30% cis-isomers), a component of crude MCHM, was rapidly absorbed from the gastrointestinal tract in male and female Charles River Sprague Dawley rats.^15^ Of the administered dose (40 or 400 mg/kg), 95% was eliminated in the urine and 2.5% in the feces 48 hours postexposure. The half-life of 1,4-cyclohexanedimethanol in plasma following a dose of 400 mg/kg was approximately 13 minutes. The metabolites of 1,4-cyclohexanedimethanol were evaluated in the urine of exposed rats and determined to be cyclohexanedicarboxylic acid (68%) and 4-hydroxymethylcyclohexanecarboxylic acid (31%). The ratio of trans- to cis-metabolites in the urine remained the same as that of the initial dose.

### Humans

There are no studies in the literature on the absorption, distribution, metabolism, or excretion of MCHM in humans.

## General Toxicity

### Experimental Animals

4-Methylcyclohexanemethanol: The acute dermal toxicity of MCHM was evaluated in male and female rats [Crl:CD(SD)BR] administered a single topical dose (0, 2, 6, or 20 mL/kg).^16^ A dermal LD_50_ value of 3.6 mL/kg was determined for both males and females.

Oral LD_50_ values for MCHM were determined from an acute oral toxicity study in rats [Crl:CD(SD)BR] administered a single dose (0, 625, 1,250, or 2,500 mg/kg) by oral gavage.^16^ LD_50_ values of 1,768 and 884 mg/kg were calculated for male and female rats, respectively.

Male and female rats exposed to MCHM (0, 25, 100, or 400 mg/kg per day) by oral gavage 5 days per week for 4 weeks exhibited increased liver weights, liver inflammation, and kidney tubular degeneration at 400 mg/kg per day.^17^ A no-observed-effect level was set at 100 mg/kg per day. The results of this study were used to establish the short-term drinking water limit of 1 ppm for MCHM.

The acute dermal toxicity of crude MCHM was evaluated in male and female rats administered a single dose of 2,000 mg/kg.^18^ Mortality occurred in two female rats, and clinical signs of toxicity in females included weakness, prostration, stumbling, red urine, and a lack of feces. Dermal effects observed in both male and female rats included erythema and desquamation. Dermal induration was observed only in female rats.

Crude 4-methylcyclohexanemethanol: Oral LD_50_ values for crude MCHM were established for both male (933 mg/kg) and female (707 mg/kg) Sprague Dawley rats (SAS:VAF[SD]) exposed to a single dose (0, 500, 1,000, or 2,000 mg/kg) by oral gavage and observed for 14 days following exposure.^19^ Mortality occurred within 24 hours in all animals treated with 2,000 mg/kg and three males and four females treated with 1,000 mg/kg. Additional clinical signs of toxicity were noted during the 14-day observation period and included weakness, prostration, stumbling, dehydration, and red urine.

Female Sprague Dawley rats [Crl:CD(SD)IGS BR] were administered a single dose (500 mg/kg) of crude MCHM via oral gavage to assess its potential to induce hematuria in this rat strain.^20^ Neither hematuria nor any additional clinical signs of toxicity were observed during a 14-day observation period.

Dimethyl 1,4-cyclohexanedicarboxylate (0%, 0.1%, 0.3%, or 1.0% in feed), a component of crude MCHM, did not induce any clinical signs of toxicity in male or female Sprague Dawley rats exposed for 4 weeks. A no-observed-adverse-effect level (NOAEL) was established at 1.0% (871 mg/kg in males, 894 mg/kg in females).^21^ An oral LD_50_ value for this chemical was reported to be greater than 5,000 mg/kg in rats.^22^

Acute exposure to 1,4-cyclohexanedimethanol (400 to 6,400 mg/kg), a component of crude MCHM, for 14 days by oral gavage induced weakness, prostration, and vasodilation in rats.^23^ Male and female Sprague Dawley rats administered 1,4-cyclohexanedimethanol in drinking water (0, 4, 8, or 12.5 mg/L) for 13 weeks demonstrated reduced survival rates, red urine, decreased food consumption, and losses in both body weight and body weight gain at 12.5 mg/L. NOAELs were established at 479 mg/kg per day for male rats and at 754 mg/kg per day for female rats. An oral LD_50_ value for 1,4-cyclohexanedimethanol was calculated at 3,200 to 6,400 mg/kg.

### Humans

No studies were identified on the general toxicity of MCHM in humans in the scientific literature. Immediately following the Elk River spill, residents of Charleston, West Virginia, reported symptoms of chemical exposures including reddened skin and erythema from dermal exposure and gastrointestinal distress (nausea, vomiting, and/or diarrhea) from ingestion of contaminated water.^24^

## Immunotoxicity

### Experimental Animals

4-Methylcyclohexanemethanol: Dermal irritation was observed in male guinea pigs [Crl:(HA)BR Hartley] 24 hours after topical administration of a single dose of 0.5 mL MCHM.^16^ Repeated dermal administration (9 applications over 11 days) of 0.5 mL MCHM in the same guinea pig model resulted in an aggravated response, as indicated by moderate erythema, moderate edema, moderate necrosis, and moderate to strong eschars.^16^

MCHM was determined to be a moderate eye irritant in New Zealand white rabbits administered a single dose (0.1 mL) to the eyes.^16^ Signs of irritation were observed 1 hour postexposure and included moderate erythema and edema of the eyelids, conjunctivae, and nictitating membranes, as well as moderate discharges.

Crude 4-methylcyclohexanemethanol: Acute dermal exposure (4 hours) to a mixture containing predominantly crude MCHM caused skin irritation, including erythema and edema, in albino rabbits [Hra:(NZW)SPF].^25^ Very slight to well-defined erythema and very slight to moderate edema were observed as early as 1 hour postexposure, and the degree of irritation increased in severity up to 72 hours postexposure.

Dermal irritation was observed at all dose levels in male and female rats exposed dermally to crude MCHM (0, 100, 500, or 2,000 mg/kg per day) for 13 days.^26^ A NOAEL for systemic toxicity was established at 2,000 mg/kg crude MCHM. Dermal exposure to a single dose of 2,000 mg/kg crude MCHM induced dermal irritation in male and female rats during the 14-day postexposure observation period.^18^ Dermal irritation was indicated by the presence of focal necrosis and eschar formation on the skin of both males and females.

Crude MCHM did not induce skin hypersensitivity (i.e., allergic contact dermatitis) when evaluated in male guinea pigs [Crl:(HA)BR VAF/Plus^®^] using the footpad method.^27^

Structure-activity relationship analysis predicted that MCHM would be positive in models for skin and eye irritation and corrosion.^28^

### Humans

No studies were available on the immunotoxicity of MCHM in humans in the scientific literature. Immediately following the Elk River chemical spill, residents of Charleston reported symptoms of chemical exposures including mild rashes and reddened skin from dermal exposure.^11^

## Study Rationale

MCHM and crude MCHM were nominated to the National Toxicology Program (NTP) for toxicity evaluation by the CDC and ATSDR following the Elk River, West Virginia, chemical spill. Due to structural alerts from in silico models of potential sensitizers and reports of reddened skin and erythema following dermal exposure to contaminated water from the spill, NTP conducted studies in mice to assess the potential immunotoxicity, specifically dermal irritancy and hypersensitivity of MCHM and crude MCHMl.