# Appendix D Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-IMM-01.

## D.1 MCHM Pure – I14001

I01 – Animal Removal Summary (32 KB)

I04 – Mean Body Weight Summary (51 KB)

I04G – Mean Body Weight Gain (45 KB)

I05 – Clinical Observations Summary (58 KB)

M01 – Irritancy Assay Summary (39 KB)

M02 – Hypersensitivity Assay Summary (32 KB)

## D.2 MCHM Pure – I14001 Individual Animal Data

Individual Animal Body Weight Data (5 MB)

Individual Animal Clinical Observation Data (24 KB)

Individual Animal Hypersensitivity Data (11 KB)

Individual Animal Irritancy (15 KB)

Individual Animal Removal Reasons (10 KB)

## D.3 MCHM Crude – I14013

I01 – Animal Removal Summary (31 KB)

I04 – Mean Body Weight Summary (65 KB)

I04G – Mean Body Weight Gain (53 KB)

I05 – Clinical Observations Summary (71 KB)

M01 – Irritancy Assay Summary (44 KB)

M02 – Hypersensitivity Assay Summary (35 KB)

## D.4 MCHM Crude – I14013 Individual Animal Data

Individual Animal Body Weight Data (5 MB)

Individual Animal Clinical Observation Data (32 KB)

Individual Animal Hypersensitivity Data (13 KB)

Individual Animal Irritancy (15 KB)

Individual Animal Removal Reasons (11 KB)

## D.5 MCHM Crude – I14013B

I01 – Animal Removal Summary (29 KB)

I04 – Mean Body Weight Summary (54 KB)

I04G – Mean Body Weight Gain (47 KB)

I05 – Clinical Observations Summary (50 KB)

M01 – Irritancy Assay Summary (40 KB)

M02 – Hypersensitivity Assay Summary (32 KB)

## D.6 MCHM Crude – I14013B Individual Animal Data

Individual Animal Body Weight Data (19 KB)

Individual Animal Clinical Observation Data (55 KB)

Individual Animal Death Details (13 KB)

Individual Animal Hypersensitivity (13 KB)

Individual Animal Irritancy (21 KB)

Individual Animal Removal Reasons (100 KB)