# Appendix C Sentinel Animal Program

## C.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that could affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

In the dermal hypersensitivity and irritancy studies of MCHM and crude MCHMl, blood samples were collected, allowed to clot and the serum was separated. All samples were processed appropriately with serology testing performed by IDEXX BioResearch (formerly Research Animal Diagnostic Laboratory, University of Missouri), Columbia, MO for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected from five female mice per time point.

Table C-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Mice
Three-day Study (2014)
Multiplex Fluorescent Immunoassay (MFI)
Ectromelia virus | 1 week postarrival
EDIM | 1 week postarrival
Lymphocytic choriomeningitis virus (LCMV) | 1 week postarrival
Mycoplasma pulmonis | 1 week postarrival
Mouse hepatitis virus (MHV) | 1 week postarrival
Mouse norovirus (MNV) | 1 week postarrival
Mouse parvovirus (MPV) | 1 week postarrival
Minute virus of mice (MVM) | 1 week postarrival
Pneumonia virus of mice (PVM) | 1 week postarrival
Reovirus 3 (REO3) | 1 week postarrival
Theiler's murine encephalomyelitis virus (TMEV) | 1 week postarrival
Sendai | 1 week postarrival
Three-day Study (2015)
Multiplex Fluorescent Immunoassay (MFI)
Ectromelia virus | 1 week postarrival
EDIM | 1 week postarrival
LCMV | 1 week postarrival
M. pulmonis | 1 week postarrival
MHV | 1 week postarrival
MNV | 1 week postarrival
MPV | 1 week postarrival
MVM | 1 week postarrival
PVM | 1 week postarrival
REO3 | 1 week postarrival
TMEV | 1 week postarrival
Sendai | 1 week postarrival

## C.2 Results

All test results were negative.