# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in NTP-2000 Rat and Mouse Ration

Table B-1 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percentage by Weight
Ground Hard Winter Wheat | 22.26
Ground #2 Yellow Shelled Corn | 22.18
Wheat Middlings | 15.0
Oat Hulls | 8.5
Alfalfa Meal (Dehydrated, 17% Protein) | 7.5
Purified Cellulose | 5.5
Soybean Meal (49% Protein) | 5.0
Fish meal (60% Protein) | 4.0
Corn Oil (without Preservatives) | 3.0
Soy Oil (without Preservatives) | 3.0
Dried Brewer’s Yeast | 1.0
Calcium Carbonate (USP) | 0.9
Vitamin Premix^a^ | 0.5
Mineral Premix^b^ | 0.5
Calcium Phosphate, Dibasic (USP) | 0.4
Sodium Chloride | 0.3
Choline Chloride (70% Choline) | 0.26
Methionine | 0.2

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table B-2 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration^a^

| Amount | Source
Vitamins
A | 4,000 IU | Stabilized vitamin A palmitate or acetate
D | 1,000 IU | D-activated animal sterol
K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl Acetate | 100 IU | –
Niacin | 23 mg | –
Folic Acid | 1.1 mg | α-Calcium pantothenate
d-Pantothenic Acid | 10 mg | –
Riboflavin | 3.3 mg | Thiamine mononitrate
Thiamine | 4 mg | –
B_12_ | 52 µg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | α-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished product.

Table B-3 Nutrient Composition of NTP-2000 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 14.9 ± 0.26 | 14.6–15.1 | 3
Crude Fat (% by Weight) | 8.2 ± 0.17 | 8.1–8.4 | 3
Crude Fiber (% by Weight) | 9.4 ± 0.14 | 9.2–9.5 | 3
Ash (% by Weight) | 6.6 ± 2.72 | 4.9–9.7 | 3
Amino Acids (% of Total Diet)
Arginine | 0.794 ± 0.070 | 0.670–0.970 | 26
Cystine | 0.220 ± 0.022 | 0.150–0.250 | 26
Glycine | 0.700 ± 0.038 | 0.620–0.800 | 26
Histidine | 0.344 ± 0.074 | 0.270–0.680 | 26
Isoleucine | 0.546 ± 0.041 | 0.430–0.660 | 26
Leucine | 1.092 ± 0.063 | 0.960–1.240 | 26
Lysine | 0.700 ± 0.110 | 0.310–0.860 | 26
Methionine | 0.408 ± 0.043 | 0.260–0.490 | 26
Phenylalanine | 0.621 ± 0.048 | 0.470–0.720 | 26
Threonine | 0.508 ± 0.040 | 0.430–0.610 | 26
Tryptophan | 0.153 ± 0.027 | 0.110–0.200 | 26
Tyrosine | 0.413 ± 0.063 | 0.280–0.540 | 26
Valine | 0.663 ± 0.040 | 0.550–0.730 | 26
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.95 ± 0.242 | 3.49–4.55 | 26
Linolenic | 0.31 ± 0.030 | 0.21–0.35 | 26
Vitamins
Vitamin A (IU/kg) | 4,670 ± 46 | 4,220–5,130 | 3
Vitamin D (IU/kg) | 1,000^a^ | – | –
α-Tocopherol (ppm) | 79.0 ± 20.42 | 27.0–124.0 | 26
Thiamine (ppm)^b^ | 8.2 ± 0.69 | 7.4–8.6 | 3
Riboflavin (ppm) | 8.1 ± 2.91 | 4.20–17.50 | 26
Niacin (ppm) | 78.9 ± 8.52 | 66.4–98.2 | 26
Pantothenic Acid (ppm) | 26.7 ± 11.63 | 17.4–81.0 | 26
Pyridoxine (ppm)^b^ | 9.7 ± 2.09 | 6.44–14.3 | 26
Folic Acid (ppm) | 1.59 ± 0.45 | 1.15–3.27 | 26
Biotin (ppm) | 0.32 ± 0.10 | 0.20–0.704 | 26
Vitamin B_12_ (ppb) | 51.8 ± 36.6 | 18.3–174.0 | 26
Choline (ppm)^b^ | 2,665 ± 631 | 1,160–3,790 | 26
Minerals
Calcium (%) | 0.918 ± 0.026 | 0.894–0.946 | 3
Phosphorus (%) | 0.553 ± 0.029 | 0.535–0.586 | 3
Potassium (%) | 0.669 ± 0.030 | 0.626–0.733 | 26
Chloride (%) | 0.386 ± 0.037 | 0.300–0.474 | 26
Sodium (%) | 0.193 ± 0.024 | 0.160–0.283 | 26
Magnesium (%) | 0.216 ± 0.057 | 0.185–0.490 | 26
Sulfur (%) | 0.170 ± 0.029 | 0.116–0.209 | 14
Iron (ppm) | 190.5 ± 38.0 | 135–311 | 26
Manganese (ppm) | 50.7 ± 9.72 | 21.0–73.1 | 26
Zinc (ppm) | 58.2 ± 26.89 | 43.3–184.0 | 26
Copper (ppm) | 7.44 ± 2.60 | 3.21–16.3 | 26
Iodine (ppm) | 0.514 ± 0.195 | 0.158–0.972 | 26
Chromium (ppm) | 0.674 ± 0.265 | 0.330–1.380 | 25
Cobalt (ppm) | 0.235 ± 0.157 | 0.094–0.864 | 24

^a^ From formulation.

^b^ As hydrochloride (thiamine and pyridoxine) or chloride (choline).

Table B-4 Contaminant Levels in NTP-2000 Rat and Mouse Ration^a^

| Mean ± Standard Deviation^b^ | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.22 ± 0.011 | 0.21–0.23 | 3
Cadmium (ppm) | 0.05 ± 0.004 | 0.046–0.053 | 3
Lead (ppm) | 0.12 ± 0.027 | 0.09–0.14 | 3
Mercury (ppm) | <0.02 | – | 3
Selenium (ppm) | 0.2 ± 0.033 | 0.17–0.23 | 3
Aflatoxins (ppb) | <5.00 | – | 3
Nitrate Nitrogen (ppm)^c^ | 11.51 ± 2.18 | 10.0–14.0 | 3
Nitrite Nitrogen (ppm)^c^ | 0.61 | – | 3
BHA (ppm)^d^ | 1.41 ± 0.72 | 1.0–2.24 | 3
BHT (ppm)^d^ | <1.0 | – | 3
Aerobic Plate Count (CFU/g) | <10 | – | 3
Coliform (MPN/g) | 3.0 ± 0.0 | 3.0–3.0 | 3
Escherichia coli (MPN/g) | <10 | – | 3
Salmonella (MPN/g) | Negative | – | 3
Total Nitrosoamines (ppb)^e^ | 14.2 ± 0.07 | 14.1–14.2 | 3
N-Nitrosodimethylamine (ppb)^e^ | 6.5 ± 2.05 | 5.0–7.9 | 3
N-Nitrosopyrrolidine (ppb)^e^ | 7.7 ± 2.12 | 6.2–9.2 | 3
Pesticides (ppm)
α-BHC | <0.01 | – | 3
β-BHC | <0.02 | – | 3
γ-BHC | <0.01 | – | 3
δ-BHC | <0.01 | – | 3
Heptachlor | <0.01 | – | 3
Aldrin | <0.01 | – | 3
Heptachlor Epoxide | <0.01 | – | 3
DDE | <0.01 | – | 3
DDD | <0.01 | – | 3
DDT | <0.01 | – | 3
HCB | <0.01 | – | 3
Mirex | <0.01 | – | 3
Methoxychlor | <0.05 | – | 3
Dieldrin | <0.01 | – | 3
Endrin | <0.01 | – | 3
Telodrin | <0.01 | – | 3
Chlordane | <0.05 | – | 3
Toxaphene | <0.10 | – | 3
Estimated PCBs | <0.20 | – | 3
Ronnel | <0.01 | – | 3
Ethion | <0.02 | – | 3
Trithion | <0.05 | – | 3
Diazinon | <0.10 | – | 3
Methyl Chlorpyrifos | 0.060 ± 0.044 | 0.020–0.107 | 3
Methyl Parathion | <0.02 | – | 3
Ethyl Parathion | <0.02 | – | 3
Malathion | 0.017 ± 0.017 | 0.021–0.247 | 3
Endosulfan I | <0.01 | – | 3
Endosulfan II | <0.01 | – | 3
Endosulfan Sulfate | <0.03 | – | 3

CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride.

^a^ All samples were irradiated.

^b^ For values less than the limit of detection, the detection limit is given as the mean.

^c^ Sources of contamination: alfalfa, grains, and fish meal.

^d^ Sources of contamination: soy oil and fish meal.

^e^ All values were corrected for percent recovery.