# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization

### A.1.1 4-Methylcyclohexanemethanol

4-Methylcyclohexanemethanol (MCHM) was obtained from TCI America (Portland, OR) in one lot (KDY3F). Crude MCHM was obtained from Eastman Chemical Company (Kingsport, TN) in one lot (TP14044373). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at MRIGlobal (Kansas City, MO). Reports on analyses performed in support of the MCHM studies are on file at the National Institute of Environmental Health Sciences.

Lot KDY3F of the pure chemical, a clear, colorless liquid, was identified as MCHM using Fourier transform infrared (FTIR) spectroscopy, Fourier transform (FT) proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy, and gas chromatography (GC) with mass spectrometry (MS) detection. In addition, the boiling point, density, and octanol:water partition coefficient were determined. All spectra were consistent with isomers of the proposed structure and literature spectra of MCHM.^50-53^ Representative FTIR and FT proton NMR spectra are presented in Figure A-1 and Figure A-2, respectively. Two components tentatively identified as cis- and trans- isomers of MCHM were observed for the test article using GC/MS. The boiling point of the test chemical was 199.4°C (consistent with a literature reference value of 202°C),^54^ the relative density was 0.9203 g/mL, and the octanol:water partition coefficient, log P, was 2.55.

Karl Fischer titration was used to determine the water content of lot KDY3F. Elemental analyses for carbon, hydrogen, and nitrogen were conducted by Galbraith Laboratories, Inc. (Knoxville, TN). The purity profile was determined using GC with flame ionization detection (FID) and two columns with differing polarities.

For lot KDY3F, Karl Fischer titration indicated 0.21% water. Elemental analyses for carbon, hydrogen, and nitrogen were consistent with the theoretical values for MCHM. GC/FID analysis by system A (Table A-1) detected two major peaks with a combined area of 99.97% of the total peak area and no impurities with areas greater than or equal to 0.05% of the total peak area. The relative areas of the two major peaks indicated that MCHM consisted of 67.99% cis- and 31.98% trans-isomers. GC/FID by system B detected two major peaks with a combined relative area of 99.83% (with relative areas of 67.80% ([cis] and 32.03% [trans] isomers), and two minor impurities totaling 0.13% of the total peak area. The overall purity of lot KDY3F was determined to be greater than or equal to 99.8%.

A chemical identity and purity screen of lot TP14044373 of the crude test chemical, a clear liquid, was performed using GC/MS. The test article was found to be a 90.35% mix of the cis- (33.45%) and trans- (56.90%) isomers of MCHM on the basis of the relative areas of the two major peaks. Six impurity components with a relative percent total area greater than or equal to 0.05% were observed, with a combined area of 9.66%. Three of these impurity components (each with an individual relative percent area greater than 1%) were tentatively identified as cyclohexanemethanol (1.82%), and a mix of the cis- and trans-isomers of 1,4-cyclohexanedimethanol (7.15%). Three minor impurities (each with an individual relative percent area between 0.05% and 1.0%) were tentatively identified as methyl 4-methylcyclohexanecarboxylate (0.50%), cis-octahydroisobenzofuran (0.13%), and 2-ethyl-1-hexanol (0.06%). The purity of lot TP14044373, relative to MCHM isomers, was estimated to be greater than 90%.

Stability studies of lot KDY3F were conducted using GC/FID by system A. These studies indicated that MCHM was stable as a bulk chemical for at least 14 days when stored in amber glass vials under an inert headspace at temperatures up to 60°C. To ensure stability, both bulk chemicals were stored at room temperature in amber glass bottles, and MCHM was stored under an inert headspace.

### A.1.2 Isoeugenol

Isoeugenol was obtained from Sigma-Aldrich, Inc. (St. Louis, MO), in one lot (05622BEV) that was used as a positive control in the initial dermal hypersensitivity and irritancy study. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Research Triangle Institute (RTI) (Research Triangle Park, NC).

The identity of lot 05622BEV, received as a clear liquid, was determined using FTIR and proton and carbon-13 NMR spectroscopy and GC/MS spectrometry. All spectra were consistent with the structure of isoeugenol and literature spectra, where available.^55-59^ An accurate molecular mass was measured using ultra-high-performance liquid chromatography (UHPLC)/time-of-flight (TOF) MS; results were within 1.2 ppm of the theoretical mass (165.0910 Da) for isoeugenol.

Karl Fischer titration was used to determine the water content of lot 05622BEV. Elemental analyses for carbon, hydrogen, and oxygen were conducted by Galbraith Laboratories, Inc. The purity was determined using GC/FID and UHPLC with photodiode array (PDA) detection. The Acquity^®^ UHPLC/PDA system consisted of a UHP liquid chromatograph, a PDA detector (254 nm), and an ethylene bridged hybrid C18 column (2.1 mm × 50 mm, 1.7 µm particle size), all from Waters Corporation (Milford, MA). The mobile phases consisted of A) 10:90:0.1 acetonitrile:deionized water:acetic acid and B) 90:10:0.1 acetonitrile:deionized water:acetic acid, programmed with a gradient starting at 100% A for 1 minute, then to 50% B in 7 minutes, then to 100% B in 1 minute, then reversed to 100% A in 1 minute, and held for 2 minutes; the flow rate was 0.6 mL/minute.

For lot 05622BEV, Karl Fischer titration indicated 0.23% water. Elemental analyses for carbon, hydrogen, and oxygen were in agreement with the theoretical values for isoeugenol. GC/FID analysis by system C indicated two major isomer peaks (totaling 98.7% of the total peak area) and two impurities (0.7% and 0.4% of the total peak area). UHPLC/PDA analysis indicated two major isomer peaks (totaling 99.1% of the total peak area) and two impurities (0.6% and 0.1% of the total peak area). The overall purity of lot 05622BEV was determined to be greater than or equal to 98.7%.

Stability studies of lot 05622BEV conducted using GC/FID by system C indicated that isoeugenol was stable as a bulk chemical for at least 14 days when stored in amber glass vials sealed with Teflon-lined caps at temperatures up to 60°C. To ensure stability, the bulk chemical was stored at room temperature under nitrogen.

### A.1.3 1-Fluoro-2,4-dinitrobenzene

1-Fluoro-2,4-dinitrobenzene was obtained from Sigma-Aldrich, Inc., in one lot (BCBN2339V) that was used as a positive control in the initial and repeat hypersensitivity and irritancy studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at RTI.

The identity of lot BCBN2339V, a clear liquid, was determined using FTIR and proton, carbon-13, and fluorine-19 NMR spectroscopy and GC/MS spectrometry. All spectra were consistent with the structure of 1-fluoro-2,4-dinitrobenzene and literature spectra, where available.^55,56,60,61^ An accurate molecular mass was measured using UHPLC/TOF MS; results were within 2.2 ppm of the theoretical mass for 1-fluoro-2,4-dinitrobenzene.

The water content of lot BCBN2339V was determined using Karl Fischer titration. Elemental analyses for carbon, hydrogen, nitrogen, oxygen, and fluorine were conducted by Galbraith Laboratories, Inc. The purity was determined using GC/FID and UHPLC with PDA detection. The Acquity^®^ UHPLC/PDA system consisted of a UHP liquid chromatograph, a PDA detector (240 nm), and an ethylene bridged hybrid C18 column (2.1 mm × 50 mm, 1.7 µm particle size), all from Waters Corporation. The mobile phases consisted of A) water and B) acetonitrile, programmed with a gradient starting at 10% B for 1 minute, then to 30% B in 7 minutes, then to 100% B in 0.5 minutes, held for 0.5 minutes, then reversed to 10% B in 0.5 minutes, and held for 2.5 minutes; the flow rate was 0.6 mL/minute.

For lot BCBN2339V, the water content was less than the limit of quantitation of 0.1%. Elemental analyses for carbon, hydrogen, nitrogen, and oxygen were in agreement with the theoretical values for 1-fluoro-2,4-dinitrobenzene; fluorine was not accurately quantitated due to interference with oxygen. GC/FID using system C indicated one major peak (99.6% of the total peak area), and two impurity peaks (0.2% each of the total peak area). UHPLC/PDA analysis indicated one major peak (99.4% of the total peak area) and three impurity peaks (0.1%, 0.2%, and 0.3% of the total peak area). The overall purity of lot BCBN2339V was determined to be greater than or equal to 99.4%.

Stability studies of lot BCBN2339V conducted using GC/FID by system C indicated that 1-fluoro-2,4-dinitrobenzene was stable as a bulk chemical for at least 14 days when stored in amber glass vials sealed with Teflon-lined caps at temperatures up to 60°C. To ensure stability, the bulk chemical was stored at room temperature under nitrogen.

## A.2 Preparation and Analysis of Dose Formulations

### A.2.1 Formulation Materials

Acetone and olive oil were obtained from multiple suppliers in multiple lots and these materials were combined with a 4:1 ratio to prepare the vehicle for the initial and repeat studies. For the repeat study, J.T. Baker Acetone (lot K30J01; Thermofisher Scientific, Waltham, MA) was analyzed using GC/FID by system D indicating a purity of 99.9%, acceptable for use in the study. Olive oil (lot 0240-0545; Welch, Holme, and Clark Co., Newark, NJ) was analyzed to determine peroxide levels using potentiometric titration (platinum combination redox electrode) using a Mettler Toledo pH meter (Mettler Toledo, Columbus, OH) and AOAC method 965.33 (AOAC, 1990). Peroxide levels were within the acceptable limit of 5 mEq/kg.

Dose formulations of the test articles and positive controls were prepared daily by mixing the appropriate amounts of each chemical with acetone:olive oil (4:1) to achieve the required concentrations (Table A-2). The dose formulations were stored in amber glass vials sealed with Teflon-lined caps at room temperature or refrigerated temperatures (1-fluoro-2,4-dinitrobenzene formulations in the repeat study only) for up to 14 days.

Stability studies of the 1% dose formulation of crude MCHM and the 0.15% dose formulation of 1-fluoro-2,4-dinitrobenzene were performed by RTI using GC/FID by systems E and C, respectively (Table A-1). Stability was confirmed for at least 14 days for these dose formulations stored in amber glass vials with minimal headspace sealed with Teflon-lined lids at room temperature and for 3 hours under simulated animal room conditions.

Analyses of the dose formulations for the initial and repeat studies were conducted by RTI using GC/FID by system E (for MCHM and crude MCHM) and system C (for the positive controls isoeugenol and 1-fluoro-2,4-dinitrobenzene). During the initial hypersensitivity and irritancy study, the dose formulations were analyzed once; two of three MCHM dose formulations were within 15% of the target concentrations and five of six crude MCHM dose formulations were within 15% of the target concentrations (Table A-3). Single dose formulations of the positive controls isoeugenol and 1-fluoro-2,4-dinitrobenzene were each found to be within 15% of the target concentrations. During the repeat dermal hypersensitivity and irritancy study, the dose formulations were analyzed once, and animal room samples of these dose formulations were also analyzed (Table A-4). All five crude MCHM dose formulations were within 15% of the target concentrations; all five animal room samples were also within 15% of the target concentrations. A single dose formulation of 1-fluoro-2,4-dinitrobenzene and its associated animal room sample were both found to be within 15% of the target concentrations.

Table A-1 Gas Chromatography Systems Used in the Dermal Hypersensitivity and Irritancy Studies of 4-Methylcyclohexanemethanol^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame Ionization | Zebron™ ZB-624, 30 m × 0.53 mm, 3.0 µm film (Phenomenex, Inc., Torrance, CA) | Helium at 5 mL/minute | 50°C for 2 minutes, then 10°C/minute to 240°C, held for 4 (purity studies) or 9 (stability studies) minutes
System B
Flame Ionization | DB-1, 30 m × 0.53 mm, 1.5 µm film (Agilent J&W, Folsom, CA) | Helium at 5 mL/minute | 50°C for 2 minutes, then 10°C/minute to 240°C, held for 4 minutes
System C
Flame Ionization | HP-5, 30 m × 0.32 mm, 0.25 µm film (Agilent Technologies, Inc., Santa Clara, CA) | Helium at 1.5 mL/minute | 50°C for 2 minutes, then 10°C/minute to 280°C, held for 5 minutes
System D
Flame Ionization | DB WAX, 30 m × 0.53 mm, 1.5 µm film (Agilent) | Helium at 10 mL/minute | 40°C for 5 minutes, then 10°C/minute to 220°C, held for 5 minutes
System E
Flame Ionization | DB-5, 30 m × 0.53 mm, 1.5 µm film (J&W Scientific, Folsom, CA) | Helium at 6 mL/minute | 50°C to 200°C at 10°C/minute, held for 5 minutes

^a^ The gas chromatographs were manufactured by Agilent Technologies, Inc. (Santa Clara, CA).

Table A-2 Preparation and Storage of Dose Formulations in the Dermal Hypersensitivity and Irritancy Studies of 4-Methylcyclohexanemethanol

4-Methylcyclohexanemethanol and Crude 4-Methylcyclohexanemethanol (Initial Study) | Crude 4-Methylcyclohexanemethanol (Repeat Study)
Preparation
The vehicle was prepared by adding the appropriate amounts of acetone and olive oil into a clear mixing bottle to obtain a 4:1 ratio. The mixing bottle was then capped and shaken for approximately 30 seconds. Dose formulations were prepared by transferring the appropriate amounts of neat or crude 4-methylcyclohexanemethanol, isoeugenol, or 1-fluoro-2,4-dinitrobenzene into volumetric flasks and bringing the flasks to final volume with the vehicle. The flasks were capped, and the contents were mixed by inversion. The dose formulations were prepared daily during the study. | The vehicle was prepared by adding the appropriate amounts of acetone and olive oil into an amber mixing bottle to obtain a 4:1 ratio. The mixing bottle was then capped and mixed by inversion. Dose formulations were prepared by transferring the appropriate amounts of neat crude 4-methylcyclohexanemethanol or 1-fluoro-2,4-dinitrobenzene into volumetric flasks and bringing the flasks to final volume with the vehicle. The flasks were capped, and the contents were mixed by inversion. The dose formulations were prepared daily during the study.
Chemical Lot Numbers
KDY3F (4-Methylcyclohexanemethanol) | TP14044373 (Crude 4-methylcyclohexanemethanol)
TP14044373 (Crude 4-methylcyclohexanemethanol) | BCBN2339V (1-Fluoro-2,4-dinitrobenzene; positive control)
05622BEV (Isoeugenol; positive control) | –
BCBN2339V (1-Fluoro-2,4-dinitrobenzene; positive control) | –
Maximum Storage Time
N/A | 14 days
Storage Conditions
The dose formulations were stored in amber glass vials sealed with Teflon-lined lids at room temperature. | The dose formulations were stored in amber glass vials sealed with Teflon-lined lids at room temperature (crude 4-methylcyclohexanemethanol) or at refrigerated temperatures (1-fluoro-2,4-dinitrobenzene).
Study Laboratory
Burleson Research Technologies, Inc. (Morrisville, NC) | Burleson Research Technologies, Inc. (Morrisville, NC)

N/A = not applicable.

Table A-3 Results of Analyses of Dose Formulations Administered to Female Mice on Day 3 in the Dermal Hypersensitivity and Irritancy Study of 4-Methylcyclohexanemethanol and Crude 4-Methylcyclohexanemethanol (Initial Study)

Date Prepared | Date Analyzed | Target Concentration (%) | Determined Concentration^a^ (%) | Difference from Target (%)
4-Methylcyclohexanemethanol
December 12, 2014 | December 12–16, 2014 | 2 | 1.54 | −23^b^
| | 20 | 21.0 | +5
| | 50 | 44.8 | −10
Crude 4-Methylcyclohexanemethanol
December 12, 2014 | December 12–16, 2014 | 1 | 0.896 | −10
| | 2 | 2.01 | +1
| | 5 | 3.84 | −23^b^
| | 20 | 19.2 | −4
| | 40 | 37.1 | −7
| | 80 | 82.0 | +3
Isoeugenol (Positive Control)
December 12, 2014 | December 12–16, 2014 | 5 | 5.30 | +6
1-Fluoro-2,4-dinitrobenzene (Positive Control)
December 12, 2014 | December 12–16, 2014 | 0.150 | 0.172 | +15

^a^ Results of triplicate analyses.

^b^ Formulation was outside the acceptable range of ± 15% of target concentration. Formulations were prepared at the study laboratory and sent for chemical analysis after the study had already been initiated.

Table A-4 Results of Analyses of Dose Formulations Administered to Female Mice in the Dermal Hypersensitivity and Irritancy Study of Crude 4-Methylcyclohexanemethanol (Repeat Study)

Date Prepared | Date Analyzed | Target Concentration (%) | Determined Concentration^a^ (%) | Difference from Target (%)
Crude 4-Methylcyclohexanemethanol
March 9–10, 2015 | March 10, 2015 | 1 | 0.985 | −2
| | 5 | 5.05 | +1
| | 25 | 24.4 | −2
| | 50 | 47.6 | −5
| | 75 | 72.5 | −3
| March 23, 2015^b^ | 1 | 1.03 | +3
| | 5 | 5.12 | +2
| | 25 | 24.6 | −2
| | 50 | 46.6 | −7
| | 75 | 72.4 | −3
1-Fluoro-2,4-dinitrobenzene (Positive Control)
March 9, 2015 | March 9, 2015 | 0.150 | 0.150 | 0
| March 23, 2015^b^ | 0.150 | 0.156 | +4

^a^ Results of triplicate analyses.

^b^ Animal room samples.

Figure A-1

Fourier Transform Infrared Absorption Spectrum of 4-Methylcyclohexanemethanol

Figure A-2

Fourier Transform Proton Nuclear Magnetic Resonance Spectrum of 4-Methylcyclohexanemethanol