# REFERENCES

Albert, R.E., French, J.E., Maronpot, R., Spalding, J., and Tennant, R. (1996). Mechanism of skin tumorigenesis by contact sensitizers: The effect of the corticosteroid fluocinolone acetonide on inflammation and tumor induction by 2,4-dinitro-1-fluorobenzene in the skin of the TG.AC (v-Ha-ras) mouse. Environ. Health Perspect. 104, 1062–1068.8930547
The Aldrich Library of Infrared Spectra (1981a). 3rd ed. (C.J. Pouchert, Ed.), Vol. 1, Spectrum 524C. Aldrich Chemical Co., Inc., Milwaukee, WI.
The Aldrich Library of Infrared Spectra (1981b). 3rd ed. (C.J. Pouchert, Ed.), Vol. 1, Spectrum 66B. Aldrich Chemical Co., Inc., Milwaukee, WI.
The Aldrich Library of FT-IR Spectra (1985). 1st ed. (C.J. Pouchert, Ed.), Vol. 1, p. 876(C). Aldrich Chemical Co., Inc., Milwaukee, WI.
Aldrich Catalog of Fine Chemicals (1990-1991) (1990). p. 442. Aldrich Chemical Co., Inc., Milwaukee, WI.
The Aldrich Library of ^13^C and ^1^H FT-NMR Spectra (1993). 1st ed., p. 1413(B). Aldrich Chemical Co., Inc., Milwaukee, WI.
Argyris, T.S. (1981). The nature of the epidermal growth produced by the first application of 12-O-tetradecanoyl-phorbol-13-acetate on the skin of mice initiated with dimethylbenzanthracene. J. Invest. Dermatol. 77, 230–234.6792294
Ashby, J., Hilton, J., Dearman, R.J., Callander, R.D., and Kimber, I. (1993). Mechanistic relationship among mutagenicity, skin sensitization, and skin carcinogenicity. Environ. Health Perspect. 101, 62–67.8513766
Aviram, A., and Aviram, I. (1983). Activation of the respiratory burst of guinea pig neutrophils by dicyclohexylcarbodiimide. FEBS Lett. 155, 205–208.6303841
Azulai, R., and Salomon, Y. (1979). Selective inactivation of hormone receptors in rat ovarian plasma membranes by N,NN-dicyclohexylcarbodiimide and light radiation. Israel J. Med. Sci. 15, 82.
Azzi, A., Casey, R.P., and Nalecz, M.J. (1984). The effect of N,NN-dicyclohexylcarbodiimide on enzymes of bioenergetic relevance. Biochim. Biophys. Acta 768, 209–226.6095905
Boorman, G.A., Montgomery, C.A., Jr., Eustis, S.L., Wolfe, M.J., McConnell, E.E., and Hardisty, J.F. (1985). Quality assurance in pathology for rodent carcinogenicity studies. In Handbook of Carcinogen Testing (H.A. Milman and E.K. Weisburger, Eds.), pp. 345–357. Noyes Publications, Park Ridge, NJ.
Boorman, G.A., Hickman, R.L., Davis, G.W., Rhodes, L.S., White, N.W., Griffin, T.A., Mayo, J., and Hamm, T.E., Jr. (1986). Serological titers to murine viruses in 90-day and 2-year studies. In Complications of Viral and Mycoplasmal Infections in Rodents to Toxicology Research and Testing (T.E. Hamm, Jr., Ed.), pp. 11–23. Hemisphere Publishing Corporation, Washington, DC.
Bucher, J.R., and Portier, C. (2004). Human carcinogenic risk evaluation, Part V: The National Toxicology Program vision for assessing the human carcinogenic hazard of chemicals. Toxicol. Sci. 82, 363–366.15456919
Cannon, R.E., Spalding, J.W., Trempus, C.S., Szczesniak, C.J., Virgil, K.M., Humble, M.C., and Tennant, R.W. (1997). Kinetics of wound-induced v-Ha-ras transgene expression and papilloma development in transgenic Tg.AC mice. Mol. Carcinog. 20, 108–114.9328441
Chadwick, D.H., and Cleveland, T.H. (1979). Isocyanates, organic. In Kirk-Othmer Encyclopedia of Chemical Technology, 3rd ed. (M. Grayson, D. Eckroth, H.F. Mark, D.F. Othmer, C.G. Overberger, and G.T. Seaborg, Eds.), Vol. 13, pp. 797–799. John Wiley and Sons, New York.
Changji, L. (1983). Acute chemical ophthalmitis caused by N,NN-dicyclohexyl carbodiimide vapor. Acta Acad. Med. Sichuan 14, 180–182.
Code of Federal Regulations (CFR) 21, Part 58.
Davies, M.G. (1983). Contact allergy to dicyclohexylcarbodiimide. Contact Dermatitis 9, 318.6225614
DiGiovanni, J. (1995). Genetic factors controlling responsiveness to skin tumor promotion in mice. Prog. Clin. Biol. Res. 391, 195–212.8532717
Dixon, W.J., and Massey, F.J., Jr. (1957). Introduction to Statistical Analysis, 2nd ed., pp. 276–278, 412. McGraw-Hill Book Company, Inc., New York.
Doi, A.M., Hailey, J.R., Hejtmancik, M., Toft, J.D., II, Vallant, M., and Chhabra, R.S. (2005). Topical application of representative multifunctional acrylates produced proliferative and inflammatory lesions in F344/N rats and B6C3F1 mice, and squamous cell neoplasms in Tg.AC mice. Toxicol. Pathol. 33, 631–640.16176922
Donehower, L.A., Harvey, M., Slagle, B.L., McArthur, M.J., Montgomery, C.A., Jr., Butel, J.S., and Bradley, A. (1992). Mice deficient for p53 are developmentally normal but susceptible to spontaneous tumours. Nature 356, 215–221.1552940
Dunn, O.J. (1964). Multiple comparisons using rank sums. Technometrics 6, 241–252.
Dunnett, C.W. (1955). A multiple comparison procedure for comparing several treatments with a control. J. Am. Stat. Assoc. 50, 1096–1121.
Eastin, W.C., Haseman, J.K., Mahler, J.F., and Bucher, J.R. (1998). The National Toxicology Program evaluation of genetically altered mice as predictive models for identifying carcinogens. Toxicol. Pathol. 26, 461–473.9715504
Ellis, H.V. (1991). Treatment for eye irritants. Chem. Eng. News 69, 2.
Flint, M.S., Salmen, R.R., Brumbaugh, K., and Tinkle, S.S. (2003). Acute stress modulates the irritant component of sensitizers in allergic contact dermatitis: Implications for exposure assessment. Toxicol. Appl. Pharmacol. 188, 50–58.12668122
French, J.E. (2004). Identification and characterization of potential human carcinogens using B6.129tm1Trp53 heterozygous null mice and loss of heterozygosity at the Trp53 locus. IARC Sci. Publ. 157, 271–287.
French, J.E., Lacks, G.D., Trempus, C., Dunnick, J.K., Foley, J., Mahler, J., Tice, R.R., and Tennant, R.W. (2001a). Loss of heterozygosity frequency at the Trp53 locus in p53-deficient (+/-) mouse tumors is carcinogen-and tissue-dependent. Carcinogenesis 22, 98–106.
French, J., Storer, R.D., and Donehower, L.A. (2001b). The nature of the heterozygous Trp53 knockout model for identification of mutagenic carcinogens. Toxicol. Pathol. 29 (Suppl.), 24–29.11695559
Funfstuck, V., Knopf, B., and Hipler, C. (1986). Contact allergy to dicyclohexylcarbodiimide [in German]. Derm. Beruf. Umwelt. 34, 110–111.2944732
Furumoto, S. (1971a). Novel method for the synthesis of carbodiimide. Nippon Kagaku Zasshi 92, 1005–1007.
Furumoto, S. (1971b). Novel method for the synthesis of carbodiimides. Nippon Kagaku Zasshi 92, 357–360.
Gart, J.J., Chu, K.C., and Tarone, R.E. (1979). Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. JNCI 62, 957–974.285297
Harris, C.C. (1996a). Structure and function of the p53 tumor suppressor gene: Clues for rational cancer therapeutic strategies. J. Natl. Cancer Inst. 88, 1442–1455.8841019
Harris, C.C. (1996b). p53 tumor suppressor gene: From the basic research laboratory to the clinic—an abridged historical perspective. Carcinogenesis 17, 1187–1198.8681432
Harris, C.C. (1996c). The 1995 Walter Hubert Lecture – molecular epidemiology of human cancer: Insights from the mutational analysis of the p53 tumour-suppressor gene. Brit. J. Cancer 73, 261–269.8562328
Hayes, B.B., Gerber, P.C., Griffey, S.S., and Meade, B.J. (1998). Contact hypersensitivity to dicyclohexylcarbodiimide and diisopropylcarbodiimide in female B6C3F1 mice. Drug Chem. Toxicol. 2, 195–206.
Hennings, H., Glick, A.B., Greenhalgh, D.A., Morgan, D.L., Strickland, J.E., Tennenbaum, T., and Yuspa, S.H. (1993). Critical aspects of initiation, promotion, and progression in multistage epidermal carcinogenesis. Proc. Soc. Exp. Biol. Med. 202, 1–8.8424089
Hoffman, T.E., and Adams, R.M. (1989). Contact allergic dermatitis to dicyclohexylcarbodiimide used in protein synthesis. J. Am. Acad. Dermatol. 21, 436–437.2526828
Hollander, M., and Wolfe, D.A. (1973). Nonparametric Statistical Methods, pp. 120–123. John Wiley and Sons, New York.
Honchel, R., Rosenzweig, B.A., Thompson, K.L., Blanchard, K.T., Furst, S.M., Stoll, R.E., and Sistare, F.D. (2001). Loss of palindromic symmetry in Tg.AC mice with a nonresponder phenotype. Mol. Carcinog. 30, 99–110.11241757
Integrated Laboratory Systems (ILS) (1990). Micronucleus Data Management and Statistical Analysis Software, Version 1.4. ILS, Inc., P.O. Box 13501, Research Triangle Park, NC 27707.
Jonckheere, A.R. (1954). A distribution-free k-sample test against ordered alternatives. Biometrika 41, 133–145.
Kaneko, J.J.. (1989). Serum proteins and the dysproteinemias. In Clinical Biochemistry of Domestic Animals (J.J. Kaneko, Ed.), 4th ed., pp. 142–165. Academic Press, Inc., San Diego, CA.
Kato, H., Hayashi, M., Fukumori, Y., and Kaneko, H. (2002). MHC restriction in contact hypersensitivity to dicyclohexylcarbodiimide. Food Chem. Toxicol. 40, 1713–1718.12176098
Kuney, J.H., Ed. (1990). Chemcyclopedia 91: The Manual of Commercially Available Chemicals, p. 408. American Chemical Society, Washington, DC.
Lang, M.H., and Hensel, O. (1987). Contact allergy to dicyclohexylcarbodiimide and N-hydroxyphthalimide [in German]. Derm. Beruf. Umwelt. 6, 212–213.
Leder, A., Kuo, A., Cardiff, R.D., Sinn, E., and Leder, P. (1990). v-Ha-ras transgene abrogates the initiation step in mouse skin tumorigenesis: Effects of phorbol esters and retinoic acid. Proc. Natl. Acad. Sci. 87, 9178–9182.2251261
MacDonald, J., French, J.E., Gerson, R.J., Goodman, J., Inoue, T., Jacobs, A., Kasper, P., Keller, D., Lavin, A., Long, G., McCullough, B., Sistare, F.D., van der Laan, J.W. (2004). The utility of genetically modified mouse assays for identifying human carcinogens: A basic understanding and path forward. The Alternatives to Carcinogenicity Testing Committee ILSI HESI. Toxicol. Sci. 77, 188–194.14657512
Mahler, J.F., Stokes, W., Mann, P.C., Takaoka, M., and Maronpot, R.R. (1996). Spontaneous lesions in aging FVB/N mice. Toxicol. Pathol. 24, 710–716.8994298
Mahler, J.F., Flagler, N.D., Malarkey, D.E., Mann, P.C., Haseman, J.K., and Eastin, W. (1998). Spontaneous and chemically induced proliferative lesions in Tg.AC transgenic and p53-heterozygous mice. Toxicol. Pathol. 26, 501–511.9715509
Maronpot, R.R., and Boorman, G.A. (1982). Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol. Pathol. 10, 71–80.28094716
The Merck Index (1989). 11th ed. (S. Budavari, Ed.), p. 488. Merck and Company, Rahway, NJ.
Morrison, D.F. (1976). Multivariate Statistical Methods, 2nd ed., pp. 170–179. McGraw-Hill Book Company, New York.
Moyer, R.C. (1990). A carbodiimide eye irritant. Chem. Eng. News 68, 2.
National Technical Information Service (NTIS) (2004). Vol. 0TS0555962. U.S. National Library of Medicine, National Institutes of Health, Department of Health and Human Services, Bethesda, MD, tehip@teh.nlm.nih.gov.
National Toxicology Program (NTP) (2005a). Toxicology Studies of Trimethylolpropane Triacrylate (Technical Grade) (CAS No. 15625-89-5) in F344/N Rats, B6C3F_1_ Mice, and Genetically Modified (FVB Tg.AC Hemizygous) Mice (Dermal Studies). Genetically Modified Mouse Report Series No. 3. NIH Publication No. 06-4450. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2005b). Toxicology Studies of Pentaerythritol Triacrylate (Technical Grade) (CAS No. 3524-68-3) in F344/N Rats, B6C3F_1_ Mice, and Genetically Modified (FVB Tg.AC Hemizygous) Mice (Dermal Studies). Genetically Modified Mouse Report Series No. 4. NIH Publication No. 06-4451. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007a). Toxicology and Carcinogenesis Studies of Diisopropylcarbodiimide (CAS No. 693-13-0) in F344/N Rats and B6C3F_1_ Mice (Dermal Studies). Technical Report No. 523, NIH Publication No. 07-4473. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2007b). Toxicology Study of Diisopropylcarbodiimide (CAS No. 693-13-0) in Genetically Modified (FVB Tg.AC Hemizygous) Mice and Carcinogenicity Study of Diisopropylcarbodiimide in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Dermal Studies). GMM Report Series No. 10, NIH Publication No. 07-4427. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
Orlowska, A., Holodowicz, E., and Drabarek, S. (1983). Comparison of dicyclohexylcarbodiimide and diisopropylcarbodiimide as coupling reagents in solid phase peptide syntheses. Pol. J. Chem. 56, 1067–1070.
Pairas, G., Camoutsis, C., and Catsoulacos, P. (1985). A new route for the synthesis of steroidal esters of carboxylic derivatives of N,N-bis(2-chloroethyl)aniline with DCC. Eur. J. Med. Chem-Chem. Ther. 20, 287–288.
Poesen, N., de Moor, A., Busschots, A., and Dooms-Goossens, A. (1995). Contact allergy to dicyclohexyl carbodiimide and diisopropyl carbodiimide. Contact Dermatitis 32, 368–369.7554893
Pritchard, J.B., French, J.E., Davis, B.J., and Haseman, J.K. (2003). The role of transgenic mouse models in carcinogen identification. Environ. Health Perspect. 111, 444–454.12676597
Rao, G.N., Haseman, J.K., and Edmondson, J. (1989a). Influence of viral infections on body weight, survival, and tumor prevalence in Fischer 344/NCr rats on two-year studies. Lab. Anim. Sci. 39, 389–393.2554057
Rao, G.N., Piegorsch, W.W., Crawford, D.D., Edmondson, J., and Haseman, J.K. (1989b). Influence of viral infections on body weight, survival, and tumor prevalence of B6C3F1 (C57BL/6N × C3H/HeN) mice in carcinogenicity studies. Fundam. Appl. Toxicol. 13, 156–164.2767355
Registry of Toxic Effects of Chemical Substances (RTECS) [database online] (1991). Carbodiimide, diisopropyl. Bethesda, MD: National Institute for Occupational Safety and Health; 1971 to present. Updated quarterly. Available from the National Library of Medicine.
Rosen, F., Roberts, N.R., Budnick, L.E., and Nichol, C.A. (1959a). Corticosteroids and transaminase activity: The specificity of the glutamic pyruvic transaminase response. Endocrinology 65, 256–264.13672148
Rosen, F., Roberts, N.R., and Nichol, C.A. (1959b). Glucocorticosteroids and transaminase activity. I. Increased activity of glutamicpyruvic transaminase in four conditions associated with gluconeogenesis. J. Biol. Chem. 234, 476–480.13641244
Sabatier, M.M., Tessier-Rochat, M., Granier, C., Van Rietschoten, J., Pedroso, E., Grandas, A., Albericio, F., and Giralt, E. (1987). Convergent solid phase peptide synthesis. VI. Synthesis by the FMOC procedure with a modified protocol of two protected segments, sequence 5-17 and 18-31 of the neurotoxin II of the scorpion Androctonus australis Hector. Tetrahedron 24, 5973–5980.
Satre, M., Lunardi, J., Pougeois, R., and Vignais, P.V. (1979). Inactivation of Escherichia coli BF1-ATPase by dicyclohexylcarbodiimide. Chemical modification of the beta-subunit. Biochemistry 18, 3134–3140.37896
Sax, N.I., and Lewis, R.J., Sr. (1987). Hawley’s Condensed Chemical Dictionary, 11th ed., p. 383. Van Nostrand Reinhold Co., New York.
Shelby, M.D., Erexson, G.L., Hook, G.J., and Tice, R.R. (1993). Evaluation of a three-exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ. Mol. Mutagen. 21, 160–179.8444144
Shirley, E. (1977). A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics 33, 386–389.884197
Simpson, J.R. (1979). Contact dermatitis due to dicyclohexylcarbodiimide. Contact Dermatitis 5, 333–334.159803
Slebioda, M., Wodecki, Z., and Kolodziejczyk, A.M. (1990). Formation of optically pure N-acyl-N,NN-dicyclohexylurea in N,NN-dicyclohexyl-carbodiimide-mediated peptide synthesis. Int. J. Pept. Protein. Res. 6, 539–541.
Spalding, J.W., Momma, J., Elwell, M.R., and Tennant, R.W. (1993). Chemically induced skin carcinogenesis in a transgenic mouse line (TG.AC) carrying a v-HA-ras gene. Carcinogenesis 14, 1335–1341.8330346
Spalding, J.W., French, J.E., Tice, R.R., Furedi-Machacek, M., Haseman, J.K., and Tennant, R.W. (1999). Development of a transgenic mouse model for carcinogenesis bioassays: Evaluation of chemically induced skin tumors in Tg.AC mice. Toxicol. Sci. 49, 241–254.10416269
Spalding, J.W., French, J.E., Stasiewicz, S., Furedi-Machacek, M., Conner, F., Tice, R.R., and Tennant, R.W. (2000). Responses of transgenic mouse lines p53(+/−) and Tg.AC to agents tested in conventional carcinogenicity bioassays. Toxicol. Sci. 53, 213–223.10696769
Takahashi, T., and Takahashi, K. (1990). N,NNDicyclohexylcarbodiimide is a specific, reversible inhibitor of proline-β-naphthylamidase. Biochem. Biophys. Res. Commun. 3, 1001–1006.
Tejedor, A., Noel, J., Vinay, P., and Gougoux, A. (1987). Metabolic effects of DCCD in suspensions of dog nephron segments. Kidney Int. 1, 403.
Tennant, R.W., French, J.E., and Spalding, J.W. (1995). Identifying chemical carcinogens and assessing potential risk in short-term bioassays using transgenic mouse models. Environ. Health Perspect. 103, 942–950.8529591
Tennant, R.W., Spalding, J., and French, J.E. (1996). Evaluation of transgenic mouse bioassays for identifying carcinogens and noncarcinogens. Mutat. Res. 365, 119–127.8898993
Tennant, R.W., Stasiewicz, S., Mennear, J., French, J.E., and Spalding, J.W. (1999). Genetically altered mouse models for identifying carcinogens. IARC Sci. Publ. 146, 123–150.
Tennant, R.W., Stasiewicz, S., Eastin, W.C., Mennear, J.H., and Spalding, J.W. (2001). The Tg.AC (v-Ha-ras) transgenic mouse: Nature of the model. Toxicol. Pathol. 29, 51–59.11695562
Tice, R.R., Erexson, G.L., Hilliard, C.J., Huston, J.L., Boehm, R.M., Gulati, D., and Shelby, M.D. (1990). Effect of treatment protocol and sample time on the frequencies of micronucleated polychromatic erythrocytes in mouse bone marrow and peripheral blood. Mutagenesis 5, 313–321.2118975
Trempus, C.S., Mahler, J.F., Ananthaswamy, H.N., Loughlin, S.M., French, J.E., and Tennant, R.W. (1998). Photocarcinogenesis and susceptibility to UV radiation in the v-Ha-ras transgenic Tg.AC mouse. J. Invest. Dermatol. 111, 445–451.9740239
TSCAPP (1991). TSCA Plant and Production Database, Chemical Information System Database, September, 1991.
Van, H., Ed. (1990). OPD Chemical Buyers Directory, 78th Annual ed., p. 424. Schnell Publishing Co., Inc., New York.
Van Miller, J.P., Garman, R.H., Hermansky, S.J., Mirsalis, J.C., and Frederick, C.B. (2003). Skin irritation, basal epithelial cell proliferation, and carcinogenicity evaluations of a representative specialty acrylate and methacrylate. Regul. Toxicol. Pharmacol. 37, 54–65.12662909
Vente, C., Menzel, S., Gutgesell, C., and Fuchs, T. (1999). Acute dermatitis after contact with dicyclohexylcarbodiimide. Am. J. Contact Dermat. 10, 51–52.10072344
White, I.R., and MacDonald, D.M. (1979). Dicyclohexyl carbodiimide sensitivity. Contact Dermatitis 4, 275–276.
Williams, D.A. (1971). A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics 27, 103–117.5547548
Williams, D.A. (1972). The comparison of several dose levels with a zero dose control. Biometrics 28, 519–531.5037867
Williams, D.A. (1986). A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics 42, 183–186.3719054
Witt, K., Tice, R.R., Shelby, M.D., Chhabra, R.S., and Zeiger, E. (1999). Induction of micronucleated erythrocytes in rodents by diisopropylcarbodiimide and dicyclohexylcarbodiimide: Dependence on exposure protocol. Environ. Mol. Mutagen. 1, 65–74.
Wright, J.T., Hansen, L., Mahler, J., Szczesniak, C., and Spalding, J.W. (1995). Odontogenic tumours in the v-HA-ras (TG.AC) transgenic mouse. Arch. Oral Biol. 40, 631–638.7575235
Zeiger, E., Anderson, B., Haworth, S., Lawlor, T., and Mortelmans, K. (1992). Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ. Mol. Mutagen. 19 (Suppl. 21), 2–141.1541260
Zschunke, E., and Folesky, H. (1975). Some effects of dicyclohexylcarbodiimide on human skin. Contact Dermatitis 3, 188.