# SUMMARY OF TECHNICAL REPORTS REVIEW SUBCOMMITTEE COMMENTS

On August 28, 2006, the draft GMM Report on the toxicology and carcinogenesis studies of dicyclohexylcarbodiimide in genetically modified mouse models received public review by the National Toxicology Program’s Board of Scientific Counselors’ Technical Reports Review Subcommittee. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. J.E. French, NIEHS, provided an overview of the NTP’s development of an alternative test model using genetically modified mice. Dr. R.S. Chhabra, NIEHS, introduced the toxicology and carcinogenesis studies of dicyclohexylcarbodiimide by discussing the uses of the chemical, the rationale for the study, and the experimental design; reporting on survival and body weight effects and compound-related neoplasms and nonneoplastic lesions in the 27- and 20-week studies in p53 and Tg.AC transgenic mice, respectively; and comparing these results to clinical pathology, reproductive, and histopathology findings in the 3-month studies in standard rodent models. The proposed conclusions were no evidence of carcinogenic activity of dicyclohexylcarbodiimide in female p53 haploinsufficient mice administered 0.75, 1.5, 3, 6, or 12 mg/kg in ethanol for 27 weeks. There were significantly increased incidences of squamous cell papilloma of the skin at the site of application in female Tg.AC hemizygous mice administered 0.75, 1.5, 3, 6, or 12 mg/kg for 20 weeks. Nonneoplastic lesions at the site of application included chronic active inflammation and epidermal hyperplasia in female p53 haploinsufficient mice and female Tg.AC hemizygous mice.

Dr. Walker, the first principal reviewer, noted that in Tg.AC mice, forestomach papillomas occurred in every treated group but not in the controls. He thought this was worthy of mention in the body of the report even though the incidences were not statistically significant.

Dr. Birt, the second principal reviewer, asked that clarification be made of the potential impact to study interpretation due to the administration of lower dose concentrations for a time during the study; she also suggested that information about potential human exposure levels be added to the introduction.

Dr. Soper, the third principal reviewer, agreed with the proposed conclusions, noting the contrast of the response in skin papillomas between the p53 and Tg.AC mouse models.

Dr. Chhabra said that comments would be added explaining why the forestomach papillomas in Tg.AC mice were discounted. Regarding the low concentrations administered during the study, he explained that the dosing formulations were initially stored at room temperature, and the occasional loss of chemical by evaporation was remedied when the formulations were refrigerated. He said that while no quantitative measures of workplace exposure in humans are in the literature, the chemical is a strong irritant and there have been a number of incidents of severe dermatitis resulting from exposure. In mice, skin irritation resulted from concentrations as low as 0.006%.

Dr. Birt moved, and Dr. Walker seconded, that the conclusions be accepted as written. The motion was approved unanimously with seven votes.