# DISCUSSION AND CONCLUSIONS

Dicyclohexylcarbodiimide and diisopropylcarbodiimide are representatives of the carbodiimide chemical class that are widely used reagents in the chemical and pharmaceutical industries, and their use is increasing in the field of bioenergetics. Dicyclohexylcarbodiimide and diisopropylcarbodiimide are used as coupling and condensation agents (especially in peptide synthesis) and as stabilizing agents. Dicyclohexylcarbodiimide currently has the greater usage, but this might change because the reaction side products of diisopropylcarbodiimide are easier to remove than those of dicyclohexylcarbodiimide. Dicyclohexylcarbodiimide and diisopropylcarbodiimide are listed in the TSCAPP database (1991), but information on specific production volumes is not available. Occupational exposure to these chemicals occurs primarily by dermal contact or inhalation. The NTP has completed dermal toxicology and carcinogenicity studies of diisopropylcarbodiimide in traditional (F344/N rats and B6C3F_1_ mice) and genetically modified (Tg.AC hemizygous mice and p53 haploinsufficient mice) animal models and reported the results in two Reports (NTP 2007a,b). In these studies, there were no treatment-related increased incidences of neoplasms in traditional or genetically modified models. In the current studies, the same genetically altered mouse models with either a loss of heterozygosity in a critical cancer suppressor gene (p53 haploinsufficient) or a gain of oncogene function (Tg.AC hemizygous) were used to determine how these animals would respond to dicyclohexylcarbodiimide exposure. The studies in these genetically modified mouse models were preceded by 3- and 13-week dermal toxicity studies in F344/N rats and B6C3F_1_ mice that were performed to characterize the toxicity of dicyclohexylcarbodiimide and select the doses for the subsequent evaluations in genetically modified animals.

Because of the paucity of acute toxicity data for dicyclohexylcarbodiimide in the literature, the doses selected for the 3-week dermal studies in F344/N rats and B6C3F_1_ mice were based on very limited information. The highest three doses (rats: 5.1, 15, 45 mg; mice: 1.7, 5, 15 mg) used in the 3-week studies were lethal to the animals. Clinical findings in the rats and mice included skin irritation at the site of application, and clinical signs of severe toxicity also occurred. The skin lesions at the site of application included epidermal hyperplasia, necrosis, and chronic inflammation in the dermis. Results of the 13-week studies suggested that B6C3F_1_ mice are generally more sensitive than F344/N rats to dicyclohexylcarbodiimide toxicity, with the major target organ being the skin at the site of application in both species. Dose-related increased incidences of inflammation and hyperplasia at the site of application were observed in both F344/N rats and B6C3F_1_ mice. The severity of these lesions was generally more pronounced in B6C3F_1_ mice than in F344/N rats. These results are consistent with published reports of the irritancy of dicyclohexylcarbodiimide; the compound has been shown to be both a skin (Zschunke and Folesky, 1975) and eye irritant in humans after occupational exposure (Changji, 1983).

In the NTP studies, the severities of acute toxicity (clinical signs of toxicity and mortality) and skin lesions at the site of application were much greater in the traditional animal models (F344/N rats and B6C3F_1_ mice) following dermal administration of dicyclohexylcarbodiimide than diisopropylcarbodiimide. The difference could be due to differences in the disposition of these chemicals after dermal application. Kinetic studies conducted by the NTP in male F344/N rats and male B6C3F_1_ mice showed that dicyclohexylcarbodiimide is partially absorbed (Appendix J); approximately 25% and 41% of dermally applied dicyclohexylcarbodiimide was absorbed by rats and mice, respectively. Seventy-two hours after dermal application, only a small percentage of the dose was found in selected tissues and the residual carcass. In contrast, kinetic studies of diisopropylcarbodiimide showed only minimal absorption ranging from 1.1% to 6.6% in F344/N rats and about 2.3% in male B6C3F_1_ mice (NTP, 2007a). Thus, increased bioavailability of dicyclohexylcarbodiimide may be responsible for its greater acute toxicity compared to that observed with diisopropylcarbodiimide.

For the studies using genetically modified mouse models, a regimen of five doses was selected to assure the availability of animals for evaluation, should there be losses in the high dose groups due to overt toxicity as seen in the F344/N rat and B6C3F_1_ mouse studies.

During the p53 mouse studies, the concentrations of dicyclohexylcarbodiimide may have been less than target concentrations for approximately 4 to 6 weeks due to possible degradation of the dose formulations in the animal room. Dermal application of dicyclohexylcarbodiimide to female p53 haploinsufficient mice resulted in chemical-related clinical signs of toxicity and histopathologic findings at the site of application that included irritation, epidermal hyperplasia, chronic active inflammation, and sebaceous gland hyperplasia. However, no incidences of neoplasms were found in any examined tissue.

In female Tg.AC hemizygous mice, nonneoplastic histopathologic findings at the site of application were similar to those seen with the p53 haploinsufficient model, but induction of dose-related incidences of squamous cell papilloma also occurred. In addition, multiplicity of papilloma increased in a dose-related manner. The dose-related increased incidences of papilloma were accompanied by skin effects such as irritation, inflammation, and/or hyperplasia at the site of application. Due to the severity of skin lesions observed in 12 mg/kg animals, application of dicyclohexylcarbodiimide was discontinued after eight applications; nevertheless, the dermal lesions persisted, and this group had the greatest incidence of papilloma. This suggests that acute or short-term exposure to highly reactive chemicals like dicyclohexylcarbodiimide may be sufficient to trigger serious adverse effects that appear later in life.

The relationship of chemical-induced skin irritation, inflammation, and hyperplasia to tumor formation is not clearly understood in either conventional or Tg.AC mouse models. A number of studies have established that induction of sustained cellular hyperplasia as seen in Tg.AC hemizygous mice treated with dicyclohexylcarbodiimide correlates well with skin tumor induction by various tumor promoting agents such as phorbol esters, several peroxides, and chrysarobin (Argyris, 1981; Hennings et al., 1993; DiGiovanni, 1995). In the current studies, it is not possible to determine how dicyclohexylcarbodiimide induced papilloma with a dose response that was similar to that of irritation, inflammation, and hyperplasia at the site of application. However, co-occurrence of these lesions is not always the case. For example, in the NTP dermal carcinogenicity studies on rotenone in Tg.AC hemizygous mice (Eastin et al., 1998), no papillomas were observed despite extensive hyperplasia and inflammation in the skin at the site of application. Another example is the 2-year dermal study of two polyfunctional acrylates that were both negative for carcinogenic activity in male C3H/HeNHsd mice despite the occurrence of proliferative effects in the skin at the site of application (Van Miller et al., 2003).

The p53 haploinsufficient mouse model has been determined to be particularly useful for in vivo testing of mutagenic carcinogens (Donehower et al., 1992; French et al., 2001a,b). In general, positive carcinogenicity results in the p53 haploinsufficient mouse model correlate better with strongly positive results in in vivo micronuclei tests than with positive results in Salmonella genotoxicity assays (Pritchard, et al., 2003; French, 2004). The Tg.AC hemizygous mouse model responds to both genotoxic and nongenotoxic carcinogens (Spalding, et al. 1999, 2000; Tennant et al., 2001). Because dicyclohexylcarbodiimide is not mutagenic in the Salmonella typhimurium gene mutation assay, the chemical was expected to be inactive in the p53 haploinsufficient strain. In male and female B6C3F_1_ mice treated dermally with dicyclohexylcarbodiimide for 13 weeks, increased frequencies of micronucleated normochromatic erythrocytes occurred in peripheral blood, suggesting that dicyclohexylcarbodiimide has a capacity for producing structural or numerical chromosomal alterations. Erythrocyte micronucleus frequencies were not determined in either of the genetically modified mouse models used in the current studies however, so no direct correlation can be made between the positive micronucleus results in B6C3F_1_ mice and the increased incidences of papilloma in dicyclohexylcarbodiimide-treated Tg.AC hemizygous mice.

The NTP studies on dicyclohexylcarbodiimide and diisopropylcarbodiimide are part of a database being established to help develop more rapid and economical carcinogenicity assays and to reduce dependency on the 2-year bioassay. These two studies and two earlier NTP studies on trimethylolpropane triacrylate (NTP, 2005a) and pentaerythritol triacrylate (NTP, 2005b) are part of a set of prospective studies performed in Tg.AC hemizygous mice (Doi et al., 2005). A tiered testing approach has been proposed recommending that agents positive for carcinogenicity in this model should be considered carcinogens, and negative studies should prompt further evaluations (Bucher and Portier, 2004). This approach was used for diisopropylcarbodiimide, which was negative in the Tg.AC hemizygous mouse and was also negative when tested by the traditional NTP 2-year study protocol (NTP, 2007a,b). Both trimethylolpropane triacrylate and pentaerythritol triacrylate were positive for carcinogenicity in the Tg.AC hemizygous mouse model, but the tiered approach was not followed for these chemicals. This is because the Tg.AC hemizygous mouse model is not yet accepted by the scientific community as definitive for identification of chemical carcinogens due to the limited information that is available on the mechanism(s) for tumor formation in this model (Bucher and Portier, 2004). As a consequence, the NTP is currently testing trimethylolpropane triacrylate in a 2-year bioassay. The characterization of a positive study in the Tg.AC hemizygous mouse as definitive for carcinogenicity as reported here with dicyclohexylcarbodiimide may be justified by the fact that some regulatory agencies have begun accepting dermal carcinogenicity studies in the Tg.AC hemizygous model in lieu of a 2-year bioassay in mice, especially for pharmaceuticals (MacDonald et al., 2004).

## Conclusions

Under the conditions of this 27-week dermal study, there was no evidence of carcinogenic activity^*^ of dicyclohexylcarbodiimide in female p53 haploinsufficient mice administered 0.75, 1.5, 3, 6, or 12 mg/kg in ethanol.

Female Tg.AC hemizygous mice dermally dosed with dicyclohexylcarbodiimide for 20 weeks had significantly increased incidences of squamous cell papilloma of the skin at the site of application.

Nonneoplastic lesions noted at the site of application included chronic active inflammation and epidermal hyperplasia in female p53 haploinsufficient mice and female Tg.AC hemizygous mice.

* Explanation of Levels of Evidence of Carcinogenic Activity is on page 9. A summary of the Technical Reports Review Subcommittee comments and the public discussion on this Report appears on page 11.