# RESULTS

## 3-Week Study in F344/N Rats

All males and females in the 15 and 45 mg groups, four 5.1 mg males, and all 5.1 mg females died before the end of the study (Table 2). Of the surviving groups, final mean body weights were similar to those of the vehicle controls, although the single surviving 5.1 mg male rat lost weight during the study. Clinical findings included skin irritation at the site of application at doses of 1.8 mg or greater. Clinical signs of toxicity in 5.1 mg or greater groups included lethargy, ruffled fur, abnormal breathing, coma, and thinness. Organ weights of surviving groups of dosed rats were generally similar to those of the vehicle control groups (Table G1).

Histologic examination of rats dosed with 5.1 mg dicyclohexylcarbodiimide or less revealed test article-related lesions of the skin at the site of application including epidermal hyperplasia, epidermal necrosis, or chronic active inflammation in the dermis (data not shown).

Dose Selection Rationale: In the 3-week rat study, the 1.8 mg/animal approximately corresponds to 12 mg/kg body weight. The doses above 1.8 mg/animal were considered to be prohibitive for 13-week studies due to mortality and clinical signs of toxicity. Therefore, for the 13-week rat study, doses selected were 0.75, 1.5, 3, 6, and 12 mg/kg in ethanol.

TABLE 2 Survival and Body Weights of F344/N Rats in the 3-Week Dermal Study of Dicyclohexylcarbodiimide

| | Mean Body Weight^b^ (g) | | | Final Weight Relative to Controls (%)
Dose (mg/animal) | Survival^a^ | Initial | Final | Change | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 207 ± 6 | 258 ± 9 | 51 ± 2
0.6 | 5/5 | 209 ± 5 | 261 ± 8 | 52 ± 3 | 101
1.8 | 5/5 | 210 ± 7 | 254 ± 9 | 45 ± 3 | 99
5.1 | 1/5^c^ | 209 ± 6 | 191 | -23 | 74
15 | 0/5^d^ | 208 ± 5 | – | –
45 | 0/5^e^ | 211 ± 9 | – | –
Female
0 | 5/5 | 144 ± 4 | 165 ± 3 | 21 ± 2
0.6 | 5/5 | 142 ± 5 | 164 ± 8 | 22 ± 3 | 99
1.8 | 5/5 | 143 ± 3 | 155 ± 5 | 12 ± 3 | 94
5.1 | 0/5^f^ | 143 ± 6 | – | –
15 | 0/5^d^ | 144 ± 4 | – | –
45 | 0/5^e^ | 141 ± 4 | – | –

a Number of animals surviving at 3 weeks/number initially in group

b Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study. Differences from the vehicle control group are not significant by Dunnett’s test.

c Day of death: 10, 11, 11, 11

d Day of death: 3 or 4

e Day of deaths: 2

f Day of death: 9, 9, 9, 10, 11

## 13-Week Study in F344/N Rats

All 12 mg/kg male and female rats died or were found moribund and sacrificed prior to day 45 (Table 3). Final mean body weight and body weight gain of 6 mg/kg males were significantly less than those of the vehicle controls (Table 3 and Figure 1). Clinical findings in 12 mg/kg males and females included skin irritation at the site of application, lethargy, tremors, ataxia, ruffled fur, a thin appearance, nasal/eye discharge, and head tilt. All 3 and 6 mg/kg males and females had irritation of the skin at the site of application.

TABLE 3 Survival and Body Weights of F344/N Rats in the 13-Week Dermal Study of Dicyclohexylcarbodiimide

| | Mean Body Weight^b^ (g) | | | Final Weight Relative to Controls (%)
Dose (mg/kg) | Survival^a^ | Initial | Final | Change | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 121 ± 3 | 330 ± 5 | 209 ± 5
0.75 | 10/10 | 120 ± 2 | 337 ± 6 | 216 ± 6 | 102
1.5 | 10/10 | 120 ± 3 | 334 ± 6 | 213 ± 5 | 101
3 | 10/10 | 120 ± 3 | 325 ± 7 | 205 ± 6 | 99
6 | 10/10 | 118 ± 2 | 300 ± 4^**^ | 182 ± 3^**^ | 91
12 | 0/10^c^ | 118 ± 3 | – | –
Female
0 | 10/10 | 102 ± 2 | 186 ± 3 | 84 ± 2
0.75 | 10/10 | 102 ± 2 | 191 ± 3 | 89 ± 2 | 103
1.5 | 10/10 | 104 ± 2 | 190 ± 4 | 86 ± 3 | 102
3 | 10/10 | 104 ± 2 | 193 ± 3 | 89 ± 2 | 104
6 | 10/10 | 103 ± 2 | 192 ± 4 | 89 ± 3 | 103
12 | 0/10^d^ | 103 ± 2 | – | –

** Significantly different (P≤0.01) from the vehicle control group by Williams’ test

a Number of animals surviving at 13 weeks/number initially in group

b Weights and weight changes are given as mean ± standard error.

c Week of death: 4, 5, 5, 6, 6, 6, 6, 6, 7, 7

d Week of death: 4, 4, 4, 5, 5, 5, 5, 6, 7, 7

FIGURE 1 Growth Curves for Male and Female F344/N Rats Administered Dicyclohexylcarbodiimide Dermally for 13 Weeks

The hematology and clinical chemistry data for rats are presented in Table F1. Evidence of an inflammatory process, indicated by increases in leukocytes, was present at all timepoints. On day 3, a neutrophilia (increased neutrophil counts) was evident in 6 mg/kg or greater males and females. On day 22, a dose-related inflammatory leukogram with a left shift, characterized by increases in leukocyte, neutrophil, and band neutrophil counts, occurred in 3 mg/kg males and 6 mg/kg or greater males and females; monocyte and eosinophil counts were also increased. However, by week 13, the inflammatory leukogram ameliorated and statistically increased neutrophil counts were observed only in 6 mg/kg females. These leukocyte changes would be consistent with the progression of an inflammatory process from the acute to chronic phases and would be a response consistent with the development of skin necrosis and chronic active inflammation observed morphologically. On day 22 and at week 13, minimal decreases in the erythron (<6%), characterized by decreases in hematocrit, hemoglobin and mean cell volume values, and erythrocyte counts, occurred in 6 mg/kg males and 12 mg/kg males and females (day 22) and 6 mg/kg females (week 13). This minimal decrease in the erythron would be consistent with erythron decreases that can develop in response to chronic inflammation and would be considered a secondary response to skin inflammation. Small decreases in albumin concentration (<20%) occurred in 3 mg/kg or greater males and 6 mg/kg or greater females on day 22 and at week 13. The albumin decrease could be a secondary response to chronic inflammation (Kaneko, 1989). Small, transient increases in serum alanine aminotransferase (ALT) activity occurred on days 3 and 22 in treated males and females; the effect abrogated by week 13, and no other marker of hepatocellular injury was affected. The cause was unknown. Because no other marker was affected and the response was transient, a transient induction of ALT production by the liver could be considered (Rosen et al., 1959a,b).

The absolute and relative weights of the heart, kidney, and liver of 3 and 6 mg/kg females were generally greater than those of the vehicle controls (Table G2). Relative weights of the heart and kidney of 3 and 6 mg/kg males were significantly greater than those of the vehicle controls. Dermal administration of dicyclohexylcarbodiimide did not affect reproductive tissue parameters in males or vaginal cytology parameters in females (Tables H1 and H2).

Test article-related gross lesions of the skin at the site of application included crusts or lesions observed in all animals dosed with 3 mg/kg or greater. At the site of application, epidermal hyperplasia occurred in all treated groups, and the incidences of this lesion were significantly increased in 3 mg/kg or greater males and 1.5 mg/kg or greater females; the incidences and severities of the lesion increased in a dose-related fashion (Tables 4, A1, and A2). In addition, chronic active inflammation occurred in most of the dosed groups, and the incidences of this lesion were significantly increased in 6 and 12 mg/kg males and 1.5 mg/kg or greater females. The incidences of sebaceous gland hyperplasia were significantly increased in 3 mg/kg or greater males and 6 and 12 mg/kg females, and the incidence of epidermal necrosis was significantly increased in male rats administered 12 mg/kg. Incidences of sebaceous gland hyperplasia were considered to be a secondary effect of inflammation rather than a direct compound effect. On the surface of the skin there was necrosis with marked acute inflammation consisting of polymorphonuclear cells with edema and coagulated serum admixed with cell debris (crusts). Deeper in the dermis, mononuclear cells mixed with proliferating fibroblasts were present, which suggested a more chronic feature of the inflammatory lesion.

Similar nonneoplastic lesions occurred in control site skin of both sexes of dosed rats, including epidermal necrosis (male: vehicle control, 0/10; 0.75 mg/kg, 0/10; 1.5 mg/kg, 0/10; 3 mg/kg, 0/10; 6 mg/kg, 1/10; 12 mg/kg, 1/10; female: 0/10, 0/10, 0/10, 0/10, 0/10, 1/10), chronic active inflammation (male: 0/10, 0/10, 0/10, 0/10, 3/10, 2/10; female: 0/10, 0/10, 0/10, 1/10, 1/10, 2/10), and epidermal hyperplasia (male: 0/10, 0/10, 0/10, 0/10, 5/10, 1/10; female: 0/10, 1/10, 1/10, 0/10, 1/10, 1/10) (Tables A1 and A2). These lesions were microscopically similar to the same lesions seen at the site of application, although most were milder in severity.

Slightly increased incidences of minimal hematopoietic cell proliferation occurred in the spleen of dosed groups of male rats (0/10, 1/10, 1/10, 1/10, 2/10, 1/10; Table A1). Increased hematopoiesis can occur with inflammatory conditions due to the physiological need for more white blood cells. Therefore, this finding was considered secondary to the skin lesions at the site of application. The incidences of diffuse bone marrow hyperplasia in 12 mg/kg males (vehicle control, 0/10; 0.75 mg/kg, 0/10; 1.5 mg/kg, 0/10; 3 mg/kg, 0/10; 6 mg/kg, 0/10; 12 mg/kg, 10/10; Table A1) and 12 mg/kg females (0/10, 0/10, 0/10, 0/10, 1/10, 9/10; Table A2) were significantly greater than those in the vehicle controls; the average severity grades for this lesion were 2.0 for 6 mg/kg females and 2.3 for 12 mg/kg males and females. As noted above, incidences of increased hematopoiesis can occur with inflammatory conditions due to the physiological need for more white blood cells, and therefore this finding was also considered secondary to the skin lesions at the site of application.

TABLE 4 Incidences of Nonneoplastic Lesions of the Skin (Site of Application) in F344/N Rats in the 13-Week Dermal Study of Dicyclohexylcarbodiimide

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Male
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Epidermis, Hyperplasia^a^ | 0 | 1 (1.0)^b^ | 3 (1.0) | 9^**^ (1.1) | 10^**^ (1.5) | 10^**^ (2.8)
Epidermis, Necrosis | 0 | 0 | 0 | 0 | 0 | 6^**^ (1.8)
Sebaceous Gland, Hyperplasia | 0 | 1 (1.0) | 1 (1.0) | 4^*^ (1.5) | 7^**^ (1.6) | 6^**^ (2.0)
Inflammation, Chronic Active | 0 | 1 (1.0) | 0 | 1 (2.0) | 7^**^ (1.0) | 9^**^ (2.9)
Female
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Epidermis, Hyperplasia | 0 | 3 (1.0) | 7^**^ (1.0) | 7^**^ (1.1) | 10^**^ (1.8) | 10^**^ (2.8)
Epidermis, Necrosis | 0 | 0 | 0 | 0 | 1 (2.0) | 3 (1.7)
Sebaceous Gland, Hyperplasia | 0 | 1 (1.0) | 0 | 0 | 5^*^ (1.0) | 7^**^ (1.4)
Inflammation, Chronic Active | 0 | 0 | 4^*^ (1.0) | 4^*^ (1.0) | 9^**^ (1.4) | 9^**^ (2.4)

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test

** P≤0.01

a Number of animals with lesion

b Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

## 3-Week Study in B6C3F_1_ Mice

One 0.6 mg female mouse and all mice in the 1.7, 5, and 15 mg groups died before the end of the study (Table 5). Final mean body weights of the 0.6 mg groups were significantly less than those of the vehicle controls, and animals in these groups generally lost weight during the study. Clinical findings included skin irritation at the site of application in all dosed groups and clinical signs of toxicity at doses of 0.6 mg or greater. Heart weights of 0.6 mg groups of mice were significantly greater than those of the vehicle controls (Table G3); thymus weights in these groups were significantly less than those of the vehicle controls.

Histopathologic examination of mice dosed with 1.7 mg dicyclohexylcarbodiimide or less revealed lesions of the skin at the site of application including epidermal hyperplasia, epidermal necrosis, and acute or chronic active dermal inflammation (data not shown).

Dose Selection Rationale: In the 3-week mouse study, 0.6 mg/animal approximately corresponds to 24 mg/kg body weight. The doses above 0.6 mg/animal were considered to be prohibitive for 13-week studies due to mortality and clinical signs of toxicity. Therefore, for the 13-week mouse study, doses selected were 1.5, 3, 6, 12, and 24 mg/kg in ethanol.

TABLE 5 Survival and Body Weights of B6C3F_1_ Mice in the 3-Week Dermal Study of Dicyclohexylcarbodiimide

| | Mean Body Weight^b^ (g) | | | Final Weight Relative to Controls (%)
Dose (mg/animal) | Survival^a^ | Initial | Final | Change | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 27.0 ± 1.1 | 28.8 ± 1.1 | 1.8 ± 0.0
0.2 | 5/5 | 26.7 ± 0.7 | 28.3 ± 0.5 | 1.6 ± 0.3 | 98
0.6 | 5/5 | 27.0 ± 0.5 | 26.0 ± 0.5^*^ | −1.0 ± 0.4^**^ | 90
1.7 | 0/5^c^ | 26.5 ± 0.6 | – | –
5 | 0/5^d^ | 26.6 ± 0.7 | – | –
15 | 0/5^e^ | 26.5 ± 0.7 | – | –
Female
0 | 5/5 | 20.6 ± 0.6 | 24.0 ± 0.5 | 3.4 ± 0.3
0.2 | 5/5 | 20.4 ± 0.5 | 23.9 ± 0.4 | 3.5 ± 0.4 | 100
0.6 | 4/5^f^ | 20.8 ± 0.7 | 21.3 ± 0.8^**^ | −0.1 ± 0.5^**^ | 89
1.7 | 0/5^g^ | 21.0 ± 0.3 | – | –
5 | 0/5^d^ | 20.8 ± 0.3 | – | –
15 | 0/5^e^ | 20.6 ± 0.6 | – | –

* Significantly different (P≤0.05) from the vehicle control group by Dunnett’s or Williams’ test

** P≤0.01

a Number of animals surviving at 3 weeks/number initially in group

b Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study.

c Day of death: 4, 4, 4, 4, 6

d Day of deaths: 2 or 3

e Day of deaths: 2

f Day of death: 15

g Day of deaths: 3

## 13-Week Study in B6C3F_1_ Mice

All 24 mg/kg male and female mice died or were found moribund and sacrificed prior to day 16 (Table 6). Final mean body weights of 6 and 12 mg/kg males and mean body weight gains of 6 and 12 mg/kg males and females were significantly less than those of the vehicle controls (Table 6 and Figure 2). With the exception of two males and six females in the 24 mg/kg group, all animals administered 6 mg/kg or greater had skin irritation at the site of application. Additional clinical findings noted in 24 mg/kg animals included ataxia, lethargy, thinness, abnormal posture, ruffled fur, and head tilt.

TABLE 6 Survival and Body Weights of B6C3F_1_ Mice in the 13-Week Dermal Study of Dicyclohexylcarbodiimide

| | Mean Body Weight^b^ (g) | | | Final Weight Relative to Controls (%)
Dose (mg/kg) | Survival^a^ | Initial | Final | Change | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 24.8 ± 0.6 | 33.7 ± 0.6 | 8.9 ± 0.4
1.5 | 10/10 | 24.8 ± 0.3 | 33.1 ± 0.7 | 8.3 ± 0.4 | 98
3 | 10/10 | 24.7 ± 0.4 | 33.0 ± 0.5 | 8.3 ± 0.2 | 98
6 | 10/10 | 24.9 ± 0.4 | 31.5 ± 0.5^**^ | 6.6 ± 0.3^**^ | 93
12 | 10/10 | 24.2 ± 0.5 | 30.4 ± 0.5^**^ | 6.2 ± 0.4^**^ | 90
24 | 0/10^c^ | 24.5 ± 0.5 | – | –
Female
0 | 10/10 | 19.6 ± 0.3 | 28.8 ± 0.9 | 9.2 ± 0.7
1.5 | 10/10 | 19.1 ± 0.5 | 28.3 ± 1.1 | 9.2 ± 0.8 | 98
3 | 10/10 | 19.1 ± 0.4 | 27.8 ± 0.5 | 8.7 ± 0.5 | 97
6 | 10/10 | 20.3 ± 0.2 | 27.7 ± 0.3 | 7.3 ± 0.3^*^ | 96
12 | 10/10 | 19.5 ± 0.3 | 26.5 ± 0.4 | 7.0 ± 0.3^**^ | 92
24 | 0/10^d^ | 19.5 ± 0.4 | – | –

* Significantly different (P≤0.05) from the vehicle control group by Williams’ test

** P≤0.01

a Number of animals surviving at 13 weeks/number initially in group

b Weights and weight changes are given as mean ± standard error.

c Week of deaths: 2

d Week of death: 2 or 3

FIGURE 2 Growth Curves for Male and Female B6C3F_1_ Mice Administered Dicyclohexylcarbodiimide Dermally for 13 Weeks

The hematology data for mice are presented in Table F2. Similar to results from the rat study, evidence of an inflammatory process was indicated by increased leukocytes at week 13. The inflammatory leukogram, characterized by increased leukocyte and neutrophil counts, occurred in 12 mg/kg males and females. These leukocyte changes would be a response consistent with the development of the skin necrosis and chronic active inflammation observed morphologically. As in rats, minimal decreases in the erythron (<10%), characterized by decreases in hematocrit and hemoglobin values and erythrocyte counts, occurred in 1.5 mg/kg or greater males and 12 mg/kg females. This minimal decrease in erythron would be consistent with the erythron decreases that can develop in response to chronic inflammation and would be considered a secondary response to skin inflammation.

Absolute and relative lung weights of 3 mg/kg or greater male mice were generally less than those of the vehicle controls, and absolute and relative heart and liver weights of 6 and 12 mg/kg female mice were generally greater than those of the vehicle controls (Table G4).

Dermal administration of dicyclohexylcarbodiimide significantly decreased the weight of the epididymis in 6 and 12 mg/kg males and significantly decreased epididymal spermatozoal motility in 6 mg/kg males (Table H3). Vaginal cytology parameters in female mice were not affected by treatment with dicyclohexylcarbodiimide (Table H4).

Chemical-related gross lesions of the skin at the site of application consisted of pink lesions, tan crusts, or areas of mottled irritation observed in all 12 mg/kg males and females, eight 24 mg/kg males, and five 24 mg/kg females. At the site of application, the incidences of epidermal hyperplasia were significantly increased in all dosed groups of males and females except those administered 24 mg/kg (not increased in this group because of early mortality) (Tables 7, B1, and B2). The incidences of chronic active inflammation were significantly increased in all dosed groups except 1.5 mg/kg females, and the incidences of epidermal necrosis were significantly increased in 24 mg/kg males and females. Epidermal necrosis also occurred in several animals administered 6 or 12 mg/kg dicylohexylcarbodiimide.

TABLE 7 Incidences of Nonneoplastic Lesions of the Skin (Site of Application) in B6C3F_1_ Mice in the 13-Week Dermal Study of Dicyclohexylcarbodiimide

| Vehicle Control | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg | 24 mg/kg
Male
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Epidermis, Hyperplasia^a^ | 0 | 7^**^ (1.0)^b^ | 10^**^ (1.0) | 10^**^ (1.4) | 10^**^ (2.3) | 0
Epidermis, Necrosis | 1 (2.0) | 0 | 0 | 0 | 2 (2.0) | 10^**^ (3.8)
Inflammation, Chronic Active | 0 | 4^*^ (1.0) | 10^**^ (1.1) | 10^**^ (1.5) | 10^**^ (1.8) | 10^**^ (2.6)
Female
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Epidermis, Hyperplasia | 0 | 5^*^ (1.0) | 9^**^ (1.3) | 10^**^ (1.8) | 10^**^ (2.7) | 3 (3.0)
Epidermis, Necrosis | 0 | 0 | 0 | 2 (2.0) | 3 (1.7) | 10^**^ (3.5)
Inflammation, Chronic Active | 0 | 1 (1.0) | 9^**^ (1.1) | 10^**^ (1.7) | 10^**^ (1.9) | 10^**^ (2.8)

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test

** P≤0.01

a Number of animals with lesion

b Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

The severities of epidermal hyperplasia and chronic active inflammation generally increased in a dose-related fashion for both sexes. The inflammation on the surface was acute, consisting of polymorphonuclear cells and cell debris mixed with coagulated serum (crusts). Deeper in the dermis, a few mononuclear cells mixed with small numbers of proliferating fibroblasts were present, which suggested a more chronic feature of the inflammatory lesion.

In control site skin, epidermal hyperplasia (male: vehicle control, 0/10; 1.5 mg/kg, 0/10; 3 mg/kg, 1/10; 6 mg/kg, 0/10; 12 mg/kg, 0/10; 24 mg/kg, 0/10; female: 0/10, 0/10, 0/10, 0/10, 3/10, 0/10) ) and inflammation and/or chronic active inflammation (male: 0/10, 1/10, 1/10, 1/10, 4/10, 0/10; female: 2/10, 0/10, 3/10, 5/10, 5/10, 1/10) occurred in some of the dosed male and female mice (Tables B1 and B2). Three of the 10 male mice administered 12 mg/kg also had epidermal necrosis or diffuse epidermal necrosis in control site skin. These lesions were microscopically similar to lesions seen at the site of application, although most were milder in severity and were due to spread of the test article by excessive grooming of the site of application.

Incidences of hematopoietic cell proliferation in the spleen were increased in most dosed groups of males (0/10, 5/10, 2/10, 7/10, 6/10, 6/10; Table B1) and females (2/10, 2/10, 7/10, 9/10, 5/10, 3/10; Table B2). Increased hematopoiesis can occur with inflammatory conditions due to the physiological need for more white blood cells. Therefore, this finding was considered secondary to the skin lesions at the site of application.

Other nonneoplastic lesions occurred primarily in the 24 mg/kg groups and included bilateral atrophy of the preputial (4/10) and clitoral glands (1/10), atrophy of the thymus (8/8 in each sex), and hemorrhage of the brain (2/10 in males, 6/10 in females) (Tables B1 and B2). These lesions occurred in mice that died prior to 16 days on study and were considered secondary effects of inanition and moribundity.

## 20-Week Study in Female Tg.AC Hemizygous Mice

### Survival

There were no deaths considered related to dicyclohexylcarbodiimide administration. Thirteen animals died or were sacrificed moribund prior to the end of the study: three each from the vehicle control and 0.75 mg/kg groups, four from the 3 mg/kg group, two from the 6 mg/kg group, and one from the 12 mg/kg group (Table 8). Overall, the survival was within the range known (70% to 100%) for the Tg.AC hemizygous mouse.

### Body Weights, Clinical Findings, and Organ Weights

Mean body weights of dosed groups of mice were similar to those of the vehicle controls (Table 8 and Figure 3). Clinical findings consisted of dose-related skin irritation at the site of application in groups treated with 1.5 mg/kg or greater. Due to the severity of skin lesions observed in 12 mg/kg animals, application of the test article was discontinued after eight dermal applications in this dose group. The absolute and relative weights of the liver in 1.5 mg/kg or greater mice were significantly greater than those in the vehicle controls (Table G5).

TABLE 8 Survival and Body Weights of Female Tg.AC Hemizygous Mice in the 20-Week Dermal Study of Dicyclohexylcarbodiimide

| | Mean Body Weight^b^ (g) | | | Final Weight Relative to Controls (%)
Dose (mg/kg) | Survival^a^ | Initial | Final | Change | Final Weight Relative to Controls (%)
0 | 7/10^c^ | 20.6 ± 0.4 | 26.8 ± 1.5 | 6.0 ± 1.2
0.75 | 7/10^d^ | 20.9 ± 0.3 | 27.7 ± 1.0 | 7.1 ± 1.0 | 103
1.5 | 10/10 | 21.0 ± 0.4 | 26.7 ± 0.7 | 5.7 ± 0.7 | 100
3 | 6/10^e^ | 20.8 ± 0.3 | 27.5 ± 0.8 | 6.3 ± 0.8 | 103
6 | 8/10^f^ | 20.5 ± 0.4 | 28.8 ± 0.9 | 8.3 ± 0.7 | 108
12^g^ | 9/10^h^ | 20.5 ± 0.4 | 27.4 ± 0.9 | 6.9 ± 0.9 | 102

a Number of animals surviving at 20 weeks/number initially in group

b Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study. Differences from the vehicle control group are not significant by Dunnett’s test.

c Week of death: 9, 12, 15

d Week of death: 7, 12, 19

e Week of death: 8, 12, 14, 17

f Week of death: 11, 18

g Treatment was discontinued after 8 days because of the severity of skin lesions at the site of application.

h Week of death: 11

FIGURE 3 Growth Curves for Female Tg.AC Hemizygous Mice Administered Dicyclohexylcarbodiimide Dermally for 20 Weeks

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the skin (site of application) and forestomach. Summaries of the incidences of neoplasms and nonneoplastic lesions in female Tg.AC hemizygous mice are presented in Tables C1 and C2, respectively.

Skin (Site of Application): Test article-related gross lesions of the skin at the site of application included irritation (0/10, 0/10, 1/10, 1/10, 2/10, 0/10) and masses and/or nodules (papillomas) (0/10, 0/10, 1/10, 4/10, 6/10, 9/10); incidences of these gross lesions increased in a dose-related fashion. At the site of application, the incidences of chronic active inflammation of the dermis and epidermal hyperplasia were significantly increased in mice administered 3 or 6 mg/kg and the incidences of squamous cell papilloma were significantly increased in mice administered 6 or 12 mg/kg (Tables 9, C1, and C2). The incidences of squamous cell papilloma and multiplicity of squamous cell papilloma increased in a dose-related manner. One squamous cell carcinoma occurred at the site of application in a 6 mg/kg mouse.

Forestomach: Six treated mice each had a grossly detectable papilloma of the forestomach (0/10, 2/10, 2/10, 1/10, 1/10, 0/10). Because the neoplasms did not increase in a dose-related manner, were not multiple, and were within historical control incidence rates for this model, the papillomas are not considered a treatment effect.

TABLE 9 Incidences of Neoplasms and Nonneoplastic Lesions of the Skin (Site of Application) in Female Tg.AC Hemizygous Mice in the 20-Week Dermal Study of Dicyclohexylcarbodiimide

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg^a^
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Dermis, Inflammation, Chronic Active^b^ | 0 | 0 | 3 (1.7)^c^ | 5^*^ (1.8) | 8^**^ (2.0) | 0
Epidermis, Hyperplasia | 0 | 0 | 0 | 6^**^ (1.8) | 7^**^ (2.0) | 1 (2.0)
Squamous Cell Papilloma, Multiple | 0 | 0 | 1 | 0 | 3 | 5^*^
Squamous Cell Papilloma (includes multiple) | 0 | 0 | 1 | 3 | 6^**^ | 8^**^
Squamous Cell Carcinoma | 0 | 0 | 0 | 0 | 1 | 0

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test

** P≤0.01

a Treatment was discontinued after 8 days because of the severity of skin lesions at the site of application.

b Number of animals with lesion

c Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

## 27-Week Study in Female p53 Haploinsufficient Mice

### Survival

Twelve animals died or were sacrificed moribund prior to the end of the study; three from the 3 mg/kg group, one from the 6 mg/kg group, and eight from the 12 mg/kg group (Table 10).

### Body Weights and Clinical Findings

Mean body weights of dosed groups of mice were similar to those of the vehicle controls (Table 10 and Figure 4). Clinical findings related to the administration of dicyclohexylcarbodiimide included irritation and ulceration of the skin at the site of application and thinness, primarily in 6 and 12 mg/kg animals. Dosing of the 6 and 12 mg/kg groups was discontinued after 11 and 8 days, respectively, because of the severity of skin lesions at the site of application.

TABLE 10 Survival and Body Weights of Female p53 Haploinsufficient Mice in the 27-Week Dermal Study of Dicyclohexylcarbodiimide

| | Mean Body Weight^b^ (g) | | | Final Weight Relative to Controls (%)
Dose (mg/kg) | Survival^a^ | Initial | Final | Change | Final Weight Relative to Controls (%)
0 | 15/15 | 18.6 ± 0.2 | 33.8 ± 1.2 | 15.3 ± 1.1
0.75 | 15/15 | 18.2 ± 0.3 | 32.1 ± 1.1 | 13.9 ± 1.1 | 95
1.5 | 15/15 | 18.3 ± 0.3 | 35.5 ± 1.2 | 17.2 ± 1.1 | 105
3 | 12/15^c^ | 18.5 ± 0.3 | 32.3 ± 1.3 | 13.8 ± 1.2 | 96
6^d^ | 14/15^e^ | 18.0 ± 0.3 | 32.0 ± 1.4 | 14.0 ± 1.2 | 95
12^f^ | 7/15^g^ | 18.1 ± 0.3 | 33.6 ± 2.4 | 15.5 ± 2.2 | 99

a Number of animals surviving at 27 weeks/number initially in group

b Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study. Differences from the vehicle control group are not significant by Dunnett’s test.

c Week of death: 7, 10, 24

d Treatment was discontinued after 11 days because of the severity of skin lesions at the site of application.

e Week of death: 5

f Treatment was discontinued after 8 days because of the severity of skin lesions at the site of application.

g Week of death: 8, 9, 9, 9, 9, 9, 9, 10

FIGURE 4 Growth Curves for Female p53 Haploinsufficient Mice Administered Dicyclohexylcarbodiimide Dermally for 27 Weeks

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions of the skin (site of application and control site) and bone marrow. Summaries of the incidences of neoplasms and nonneoplastic lesions in female p53 haploinsufficient mice are presented in Tables D1 and D2, respectively.

Skin (Site of Application): Chemical-related gross lesions of the skin at the site of application included reddening (0/15, 0/15, 0/15, 0/15, 0/15, 5/15), red scars (0/15, 0/15, 0/15, 0/15, 0/15, 1/15), red crusts (0/15, 0/15, 0/15, 0/15, 0/15, 2/15), and ulcers (0/15, 0/15, 0/15, 2/15, 1/15, 2/15). At the site of application, the incidences of focal epidermal hyperplasia were significantly increased in mice administered 1.5, 3, or 12 mg/kg, and the severity of the lesion increased in a dose-related manner (Tables 11 and D2). In addition, incidences of focal chronic active inflammation of the dermis in 3 or 12 mg/kg mice and focal ulcer and focal chronic active inflammation of the subcutaneous tissue in 12 mg/kg mice were significantly increased. Focal hyperplasia of the sebaceous gland occurred in mice administered 3 or 12 mg/kg. Decreased incidences of these skin lesions in the 6 mg/kg animals compared to 3 mg/kg animals are most likely due to the decreased number of dosing days for the 6 mg/kg group (11 days) compared to the 3 mg/kg group (27 weeks). Incidences of minimal to mild focal sebaceous gland hyperplasia were considered a secondary effect of inflammation at the site of application.

Skin (Control Site): Incidences of focal dermal chronic active inflammation (0/15, 0/15, 0/15, 3/15, 1/15, 2/15), focal subcutaneous chronic active inflammation (0/15, 0/15, 0/15, 1/15, 0/15, 2/15), focal epidermal hyperplasia (0/15, 0/15, 0/15, 2/15, 0/15, 1/15), focal ulceration (0/15, 0/15, 0/15, 1/15, 0/15, 2/15), and focal sebaceous gland hyperplasia (0/15, 0/15, 0/15, 1/15, 0/15, 1/15) in control site skin were less than those seen at the site of application and were less severe (Table D2).

Bone Marrow: Myeloid cell hyperplasia of the bone marrow occurred in the 3 mg/kg or greater groups (0/15, 0/15, 0/15, 3/15, 1/14, 8/15), and the incidence of this lesion was significantly increased in the 12 mg/kg group (Table D2). Increased hematopoiesis can occur with inflammatory conditions due to the physiological need for more white blood cells. Therefore, the increased incidence of myeloid cell hyperplasia is considered a reactive change in response to the skin lesions at the site of application.

TABLE 11 Incidences of Nonneoplastic Lesions of the Skin (Site of Application) in Female p53 Haploinsufficient Mice in the 27-Week Dermal Study of Dicyclohexylcarbodiimide

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg^a^ | 12 mg/kg^b^
Number Microscopically Examined | 15 | 15 | 15 | 15 | 15 | 15
Dermis, Inflammation, Chronic Active, Focal^c^ | 1 (1.0)^d^ | 0 | 0 | 13^**^(1.3) | 2 (1.0) | 9^**^ (3.3)
Epidermis, Hyperplasia, Focal | 0 | 1 (1.0) | 5^*^ (1.0) | 11^**^ (1.5) | 1 (2.0) | 8^**^ (3.0)
Sebaceous Gland, Hyperplasia, Focal | 0 | 0 | 0 | 3 (1.7) | 0 | 3 (2.0)
Ulcer, focal | 0 | 0 | 0 | 2 (4.0) | 1 (4.0) | 8^**^ (3.9)
Subcutaneous Tissue, Inflammation, Chronic Active, Focal | 0 | 0 | 0 | 2 (3.0) | 0 | 8^**^ (3.6)

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test

** P≤0.01

a Treatment was discontinued after 11 days because of the severity of skin lesions at the site of application.

b Treatment was discontinued after 8 days because of the severity of skin lesions at the site of application.

c Number of animals with lesion

d Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

## Genetic Toxicology

Dicyclohexylcarbodiimide was not mutagenic in Salmonella typhimurium strains TA97, TA98, TA100, or TA1535, with or without induced rat or hamster liver S9 activation enzymes (Table E1). Results of in vivo tests for chromosomal effects in F344/N rats and B6C3F_1_ mice are discussed in detail by Witt et al. (1999), and the data are presented in Tables E2 and E3, respectively. Negative results were obtained in an acute exposure bone marrow micronucleus test in male F344/N rats using an intraperitoneal injection route of chemical administration (Table E2). Dicyclohexylcarbodiimide, administered dermally for 13 weeks, induced significant increases in the frequency of micronucleated normochromatic erythrocytes (NCEs) in peripheral blood of male B6C3F_1_ mice, based on results of a trend test analysis (P=0.003), although none of the treated groups showed a significant increase in the frequency of micronucleated NCEs compared to the vehicle control group (Table E3). In female B6C3F_1_ mice, the frequencies of micronucleated NCEs in all treated groups were greater than that in the vehicle controls, but the increase was significant only in the 3 mg/kg group, and the trend was not significant; results in female B6C3F_1_ mice were concluded to be weakly positive. There was no effect of treatment on the percentage of polychromatic erythrocytes in peripheral blood of male or female B6C3F_1_ mice, suggesting no measurable dicyclohexylcarbodiimide-induced toxicity to the bone marrow.