# MATERIALS AND METHODS

## Procurement and Characterization

### Dicyclohexylcarbodiimide

Dicyclohexylcarbodiimide, lot 00929TZ, was obtained from Aldrich Chemical Company (Milwaukee, WI) and was used in the 3-, 13-, and 20-week studies; lot 60104-1 was obtained from Chem-Impex International (Wood Dale, IL) and was used in the 27-week study. Identity and purity analyses were conducted by the analytical chemistry laboratory, Midwest Research Institute (Kansas City, MO), and by the study laboratories, Microbiological Associates, Inc. (Bethesda, MD; 3-, 13-, and 20-week studies), and BioReliance Corporation (Rockville, MD; 27-week study) (Appendix I). Reports on analyses performed in support of the dicyclohexylcarbodiimide studies are on file at the National Institute of Environmental Health Sciences.

The chemical, a colorless crystalline material, was identified as dicyclohexylcarbodiimide by the study laboratories using infrared spectroscopy (lots 00929TZ and 60104-1) and by the analytical chemistry laboratory using infrared and proton nuclear magnetic resonance (NMR) spectroscopy (lot 60104-1). All spectra were consistent with the literature spectra (Aldrich, 1981a, 1985, 1993).

The purity of lot 00929TZ was determined by the study laboratory using gas chromatography (GC). The purity of lot 60104-1 was determined by the analytical chemistry laboratory using high-performance liquid chromatography (HPLC), and purity relative to a frozen reference standard of the same lot was measured by the study laboratory using HPLC.

For lot 00929TZ, GC indicated one major peak, three major impurities (ranging from 0.08% to 0.27% of the total peak area), and two minor impurities. The overall purity of lot 00929TZ was determined to be 99.5%. For lot 60104-1, HPLC indicated a major peak and six impurity peaks with a combined area of 1.69% relative to the total peak area. The overall purity of lot 60104-1 was estimated to be greater than 98%.

To ensure stability, the bulk chemical was stored at room temperature, under a nitrogen head space, protected from light. Periodic analyses of the bulk chemical were performed by the study laboratories during the studies using GC (lot 00929TZ) and HPLC (lot 60104-1); no degradation of the bulk chemical was detected.

### Anhydrous Ethanol

Anhydrous ethanol was obtained from Pharmco Products, Inc. (Brookfield, CT). Identity and purity analyses of all lots used in the 27-week study were conducted by the study laboratory. The chemical, a clear liquid, was identified as ethanol using IR spectroscopy; the sample spectra were consistent with a literature spectrum (Aldrich, 1981b). The purity of each lot was analyzed using GC. The overall purity of each analyzed lot was determined to be greater than 99.9%.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared twice for the 3-week studies, at least every 2 weeks for the 13-week studies, every 3 weeks for the 20-week study, or monthly for the 27-week study by mixing dicyclohexylcarbodiimide and anhydrous ethanol to give the required concentration. The dose formulations were stored in sealed vials under a headspace of inert gas for up to 28 days (3- and 13-week studies) or 35 days (20- and 27-week studies) at room temperature for the 3-, 13-, and 20-week studies, and until April 1, 1999 (week 13), for the 27-week study; subsequent storage for the 27-week study was at −20° C.

Because the dose formulations were true solutions of the test article in ethanol, homogeneity studies were not performed. Stability studies of 0.38, 2, and 7 mg/mL dose formulations of lot 00929TZ were conducted by the study laboratory using GC. Stability was confirmed for up to 35 days for dose formulations stored at room temperature in sealed containers under a nitrogen headspace and for up to 3 hours when exposed to light and air at room temperature.

Periodic analyses of the dose formulations of dicyclohexylcarbodiimide were conducted by the study laboratories using GC. Dose formulations were analyzed once for the 3-week studies; all five dose formulations were within 10% of the target concentrations (Table I4). Animal room samples were also analyzed; all 10 animal room samples for rats and mice were within 10% of the target concentrations. During the 13-week studies, the dose formulations were analyzed at the beginning, midpoint, and end of the studies; animal room samples of these dose formulations were also analyzed (Table I5). Of the dose formulations analyzed, all 15 for rats and all 15 for mice were within 10% of the target concentration; all 13 animal room samples for rats and 12 of 13 for mice were within 10% of the target concentrations. One aberrant mouse animal room sample was determined to be due to evaporation from an inadequately sealed vial. Dose formulations were analyzed at the beginning, midpoint, and end of the 20-week study, and animal room samples of these dose formulations were also analyzed; all 15 dose formulations and all 13 animal room samples were within 10% of the target concentrations (Table I6). During the 27-week study, the dose formulations were analyzed four times; animal room samples were also analyzed. All 14 dose formulations analyzed were within 10% of the target concentrations; 8 of 14 animal room samples were not within 10% of target concentrations (Table I7). Unusual degradation was observed in the animal room samples from the formulations prepared on February 24, 1999, and March 24, 1999. Attempts to discover the cause of the degradation in the formulations were not conclusive, but the most likely cause, water in the anhydrous ethanol, was eliminated. Starting on April 2, 1999, all dose formulations were stored at −20° C as a further precaution against degradation.

## 3-Week Studies in F344/N Rats and B6C3F_1_ Mice

Male and female F334/N rats and B6C3F_1_ mice were obtained from Taconic Laboratory Animals and Services (Germantown, NY). On receipt, the animals were approximately 5 weeks old. Rats were quarantined for 26 days and were 9 weeks old on the first day of the study. Mice were quarantined for 20 days and were 8 weeks old on the first day of the study. Before the studies began, two male and two female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. Groups of 5 male and 5 female rats and mice received dermal applications of 0, 2, 6, 17, 50, or 150 mg dicyclohexylcarbodiimide per mL of ethanol, 5 days per week for 16 days. Fixed volumes of ethanol (rats, 0.3 mL; mice, 0.1 mL) were applied to the clipped dorsal skin, from the posterior of the scapulae to the base of the tail, resulting in daily doses of 0, 0.6, 1.8, 5.1, 15, or 45 mg dicyclohexylcarbodiimide per rat and 0, 0.2, 0.6, 1.7, 5, or 15 mg per mouse. Rats and mice were housed individually, with feed and water available ad libitum. The animals were weighed and clinical findings were recorded initially, on day 8, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1.

Necropsies were performed on all rats and mice. The adrenal gland, heart, right kidney, liver, lung, right testis, and thymus were weighed. Histopathologic examinations were performed on rats administered 0, 0.6, 1.8, and 5.1 mg/animal and mice administered 0, 0.2, 0.6, and 1.7 mg/animal. Table 1 lists the tissues and organs examined.

## 13-Week Studies in F344/N Rats and B6C3F_1_ Mice

Male and female F334/N rats and B6C3F_1_ mice were obtained from Taconic Laboratory Animals and Services (Germantown, NY). On receipt, the animals were approximately 5 weeks old. Animals were quarantined for 12 to 15 days and were 7 weeks old on the first day of the studies. Before initiation of the studies, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. Blood was collected from five male and five female vehicle control rats and sentinel mice at study termination. The sera were analyzed for antibody titers to rodent viruses (Boorman et al., 1986; Rao et al., 1989a,b); all results were negative.

Groups of 10 male and 10 female core study rats received dermal applications of 0, 0.75, 1.5, 3, 6, or 12 mg dicyclohexylcarbodiimide/kg body weight in ethanol, 5 days per week for 13 weeks; groups of 10 male and 10 female clinical pathology rats were given the same doses for 22 days. Groups of 10 male and 10 female mice received dermal applications of 0, 1.5, 3, 6, 12, or 24 mg/kg in ethanol, 5 days per week for 13 weeks. Dosing volumes of 0.5 and 2 mL/kg for rats and mice, respectively, were applied to a clipped dorsal area from the posterior of the scapulae to the base of the tail. Rats and mice were housed individually, with feed and water available ad libitum. Body weights and clinical findings were recorded initially, weekly, and at the end of the studies for core study animals. Details of the study design and animal maintenance are summarized in Table 1.

Blood was collected for hematology and clinical chemistry analyses from clinical pathology study rats on days 3 and 22 and from core study rats at study termination. Blood was collected for hematology analyses from mice at study termination. At all time points, the animals were anesthetized with a 70% CO_2_/30% O_2_ mixture and blood was collected from the retroorbital sinus. Blood for hematology analyses was placed in tubes containing EDTA as the anticoagulant. Erythrocyte, platelet, and leukocyte counts, automated hematocrit values, hemoglobin concentration, mean cell volume, mean cell hemoglobin, and mean cell hemoglobin concentration were determined using a Serono-Baker System 9010 hematology analyzer (Serono-Baker Diagnostics, Allentown, PA). Manual hematocrit determinations were performed using an Adams Microhematocrit Centrifuge, Model CT2900 (Becton, Dickinson and Company, Franklin Lakes, NJ). Differential leukocyte counts and erythrocyte and leukocyte morphologies were determined microscopically from blood smears stained with a modified Wright’s stain on a Hema-Tek slide stainer (Miles Laboratory, Ames Division, Elkhart, IN). Reticulocytes were stained with new methylene blue and counted microscopically. For clinical chemistry analyses, blood samples were placed into untreated serum separator tubes, centrifuged, and the serum samples were analyzed using a Hitachi 717 chemistry analyzer (Boehringer Mannheim, Indianapolis, IN) and commercially available reagents. The parameters measured are listed in Table 1.

At the end of the 13-week studies, samples were collected for sperm motility and vaginal cytology evaluations on 0, 1.5, 3, and 6 mg/kg core study rats and 0, 3, 6, and 12 mg/kg mice. The parameters evaluated are listed in Table 1. For 12 consecutive days prior to scheduled terminal sacrifice, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were collected and stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65° C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all core study animals. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 5 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed on 0, 6, and 12 mg/kg core study rats and 0, 12, and 24 mg/kg mice. Selected tissues were examined in the remaining dosed groups. Table 1 lists the tissues and organs routinely examined.

Upon completion of the laboratory pathologist’s histopathologic evaluation, the slides, paraffin blocks, and residual wet tissues were sent to the NTP Archives for inventory, slide/block match, and wet tissue audit. The slides, individual animal data records, and pathology tables were sent to an independent pathology laboratory where quality assessment was performed. Results were reviewed and evaluated by the NTP Pathology Working Group (PWG); the final diagnoses represent a consensus of contractor pathologists and the PWG. Details of these review procedures have been described by Maronpot and Boorman (1982) and Boorman et al. (1985).

## 20-Week Study in Female Tg.AC Hemizygous Mice

Female FVB/N-TgN(v-Ha-ras)Led (Tg.AC) hemizygous mice were obtained from Taconic Laboratory Animals and Services, Inc. (Germantown, NY). On receipt, the mice were 4 weeks old. Animals were quarantined for 14 days and were 6 weeks old on the first day of the study. Before the study began, five mice were randomly selected for parasite evaluation and gross observation for evidence of disease. Blood was collected from five randomly selected vehicle control mice at study termination and from one mouse that was sacrificed moribund during the study. The sera were analyzed for antibody titers to rodent viruses; all results were negative.

Doses for the 20-week study in Tg.AC hemizygous mice were based on the results of 13-week toxicity studies performed in B6C3F_1_ mice. Groups of 10 female mice received dermal applications of 0, 0.75, 1.5, 3, 6, or 12 mg/kg in ethanol, 5 days per week for up to 20 weeks. Due to the severity of skin lesions observed in 12 mg/kg animals, the application of dicyclohexylcarbodiimide was discontinued after eight dermal applications in this group. A dosing volume of 2 mL ethanol per kg body weight was applied to the center of a shaved dorsal area posterior of the scapulae to the base of the tail, with the application site no greater than 10% of the animal’s body surface. From June 26, 1995, doses were applied anterior or posterior to the original site if lesions were observed at the original site. Animals were housed individually, with feed and water available ad libitum. Body weights and clinical findings were recorded initially, weekly, and at the end of the study. Details of the study design and animal maintenance are summarized in Table 1.

Necropsies were performed on all animals. The heart, right kidney, liver, lung, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed on all vehicle control mice, all 12 mg/kg mice, and all mice that died before the end of the study. In addition, the skin was examined in all remaining dosed groups. Table 1 lists the tissues and organs routinely examined.

Upon completion of the laboratory pathologist’s histopathologic evaluation, the slides, paraffin blocks, and residual wet tissues were sent to the NTP Archives for inventory, slide/block match, and wet tissue audit. The slides, individual animal data records, and pathology tables were sent to an independent pathology laboratory where quality assessment was performed. Results were reviewed and evaluated by the NTP Pathology Working Group (PWG); the final diagnoses represent a consensus of contractor pathologists and the PWG.

## 27-Week Study in Female p53 Haploinsufficient Mice

Female B6.129-Trp53^tm1Brd^ (N5) haploinsufficient mice were obtained from Taconic Farms, Inc. (Germantown, NY). On receipt, the animals were approximately 6 weeks old. Animals were quarantined for 14 days and were 8 weeks old on the first day of the study. Before initiation of the study, five mice were randomly selected for parasite evaluation and gross observation for evidence of disease. Blood was collected at study termination from five randomly selected vehicle control mice. The sera were analyzed for antibody titers to rodent viruses; all results were negative.

Doses for the 27-week study in p53 haploinsufficient mice were based on the results of 13-week toxicity studies performed in B6C3F_1_ mice. Groups of 15 female mice received dermal applications of 0, 0.75, 1.5, 3, 6, or 12 mg/kg in ethanol, 5 days per week for up to 27 weeks. Dosing of the 6 and 12 mg/kg groups was discontinued after 11 and 8 days, respectively, because of the severity of skin lesions at the site of application. The dosing volume of 2 mL/kg was applied to a shaved dorsal area posterior of the scapulae to the base of the tail. Mice were housed individually, with feed and water available ad libitum. Body weights and clinical findings were recorded initially, weekly, and at the end of the study. Details of the study design and animal maintenance are summarized in Table 1.

Necropsies were performed on all animals. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Histopathologic examinations were performed on all animals. Table 1 lists the tissues and organs routinely examined.

Upon completion of the laboratory pathologist’s histopathologic evaluation, the slides, paraffin blocks, and residual wet tissues were sent to the NTP Archives for inventory, slide/block match, and wet tissue audit. The slides, individual animal data records, and pathology tables were sent to an independent pathology laboratory where quality assessment was performed. The final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist, NTP Pathology Working Group chairperson, and the NTP pathologist.

TABLE 1 Experimental Design and Materials and Methods in the Dermal Studies of Dicyclohexylcarbodiimide

3-Week Studies | 13-Week Studies | 20-Week Study | 27-Week Study
Study Laboratory
Microbiological Associates, Inc. (Bethesda, MD) | Microbiological Associates, Inc. (Bethesda, MD) | Microbiological Associates, Inc. (Bethesda, MD) | BioReliance Corporation (Rockville, MD)
Strain and Species
F344/N rats; B6C3F_1_ mice | F344/N rats; B6C3F_1_ mice | FVB/N-TgN(v-Ha-ras)Led (Tg.AC) hemizygous mice | B6.129-Trp53^tm1Brd^ (N5) haploinsufficient mice
Animal Source
Taconic Laboratory Animals and Services (Germantown, NY) | Taconic Laboratory Animals and Services (Germantown, NY) | Taconic Laboratory Animals and Services (Germantown, NY) | Taconic Laboratory Animals and Services (Germantown, NY)
Time Held Before Studies
Rats: 26 days; Mice: 20 days | Rats: 12 days (males) or 13 days (females); Mice: 14 days (males) or 15 days (females)
Average Age When Studies Began
Rats: 9 weeks; Mice: 8 weeks | 7 weeks | 6 weeks | 8 weeks
Date of First Dose
Rats: June 28, 1994; Mice: June 29, 1994 | Rats: September 20 (males) or September 21 (females), 1994; Mice: September 22 (males) or September 23 (females), 1994
Duration of Dosing
5 doses per week for 16 days | 5 doses per week for 13 weeks | 5 doses per week for 2 (12 mg/kg) or 20 weeks | 5 doses per week for 2 weeks (12 mg/kg), 3 weeks (6 mg/kg), or 27 weeks
Date of Last Dose
Rats: July 13, 1994; Mice: July 14, 1994 | Rats: December 19 (males) or December 20 (females), 1994; Mice: December 21 (males) or December 22 (females), 1994 | June 26 (12 mg/kg) or November 1, 1995
Necropsy Dates
Rats: July 14, 1994; Mice: July 15, 1994 | Rats: December 20 (males) or December 21 (females), 1994; Mice: December 22 (males) or December 23 (females), 1994
Average Age at Necropsy
Rats: 11 weeks; Mice: 10 weeks | Rats: 20 (males) or 20 (females) weeks; Mice: 20 weeks | 27 weeks | 34 weeks
Size of Study Groups
5 males and 5 females | 10 males and 10 females | 10 females | 15 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 3-week studies | Same as 3-week studies | Same as 3-week studies
Animals per Cage
1 | 1 | 1 | 1
Method of Animal Identification
Tail tattoo | Tail tattoo | Tail tattoo | Tail tattoo
Diet
NIH-07 open formula pelleted diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed weekly | Same as 3-week studies | Same as 3-week studies | Irradiated NTP-2000 open formula pelleted diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed weekly
Water
Tap water (Washington Suburban Sanitary Commission Potomac Plant) via automatic watering system (Edstrom Industries; Waterford, WI) available ad libitum | Same as 3-week studies | Same as 3-week studies | Same as 3-week studies
Cages
Polycarbonate (Lab Products, Inc., Seaford, DE), changed once weekly | Same as 3-week studies | Same as 3-week studies | Same as 3-week studies
Bedding
Heat-treated Sani-chips® (P.J. Murphy Forest Products Corp., Montville, NJ) changed once weekly | Same as 3-week studies | Same as 3-week studies | Same as 3-week studies
Cage Filters
Remay 2016 (Snow Filtration, West Chester, OH), changed once weekly | Same as 3-week studies | Same as 3-week studies | Same as 3-week studies
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated once every 2 weeks | Same as 3-week studies | Same as 3-week studies | Same as 3-week studies
Animal Room Environment
Temperature: 72° ± 3° F | Temperature: 72° ± 3° F | Temperature: 72° ± 3° F | Temperature: 72° ± 3° F
Relative humidity: 50% ± 15% | Relative humidity: 50% ± 15% | Relative humidity: 50% ± 15% | Relative humidity: 50% ± 15%
Room fluorescent light: 12 hours/day | Room fluorescent light: 12 hours/day | Room fluorescent light: 12 hours/day | Room fluorescent light: 12 hours/day
Room air changes: at least 10/hour | Room air changes: at least 10/hour | Room air changes: at least 10/hour | Room air changes: at least 10/hour
Doses
Rats: 0, 0.6, 1.8, 5.1, 15, or 45 mg/animal in 0.3 mL ethanol; Mice: 0, 0.2, 0.6, 1.7, 5, or 15 mg/animal in 0.1 mL ethanol | Rats: 0, 0.75, 1.5, 3, 6, or 12 mg/kg body weight in 0.5 mL/kg ethanol; Mice: 0, 1.5, 3, 6, 12, or 24 mg/kg in 2 mL/kg ethanol | Mice: 0, 0.75, 1.5, 3, 6, or 12 mg/kg body weight administered in ethanol (2 mL/kg) 5 days per week | Mice: 0, 0.75, 1.5, 3, 6, or 12 mg/kg body weight administered in ethanol (2 mL/kg) 5 days per week
Type and Frequency of Observation
Observed twice daily; animals were weighed and clinical findings recorded initially, on day 8, and at the end of the studies. | Observed twice daily; animals were weighed and clinical findings recorded initially, weekly, and at the end of the studies. | Observed twice daily; animals were weighed and clinical findings recorded initially, weekly, and at the end of the study | Observed twice daily; animals were weighed and clinical findings recorded initially, weekly, and at the end of the study
Method of Sacrifice
Carbon dioxide asphyxiation | Same as 3-week studies | Same as 3-week studies | Same as 3-week studies
Necropsy
Necropsies were performed on all animals. Organs weighed were the adrenal gland, heart, right kidney, liver, lung, right testis, and thymus. | Necropsies were performed on all core study animals. Organs weighed were the heart, right kidney, liver, lung, right testis, and thymus. | Necropsies were performed on all animals. Organs weighed were the heart, right kidney, liver, lung, and thymus. | Necropsies were performed on all animals.
Clinical Pathology
None | Blood was collected from the retroorbital sinus of special study rats on days 3 and 22 and from all core study rats and mice surviving to the end of the studies for hematology and clinical chemistry (rats only) determinations.; Hematology: automated and manual hematocrit; erythrocyte, reticulocyte, nucleated erythrocyte, and platelet counts; hemoglobin concentration; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; leukocyte count and differentials; Clinical chemistry: urea nitrogen, creatinine, total protein, albumin, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and bile acids.
Histopathology
Histopathology was performed on vehicle control, 0.6, 1.8, and 5.1 mg/animal rats and vehicle control, 0.2, 0.6, and 1.7 mg/animal mice. In addition to gross lesions and tissue masses, the following tissues were examined: brain, kidney, liver, lung, skin, and spinal cord. | Complete histopathology was performed on vehicle control, 6, and 12 mg/kg core study rats, and vehicle control, 12, and 24 mg/kg mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, gallbladder (mice), heart with aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, skin, spleen, stomach (forestomach and glandular), testis with epididymis and seminal vesicle, thymus, thyroid gland, trachea, urinary bladder, uterus, and Zymbal’s gland. In addition, the bone marrow of rats, spleen of male rats and male and female mice, and the skin of rats and mice were examined in all remaining dosed groups. | Complete histopathology was performed on all vehicle control and 12 mg/kg animals and all animals that died early. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, gallbladder, heart with aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, salivary gland, skin, spleen, stomach (forestomach and glandular), thymus, thyroid gland, trachea, urinary bladder, and uterus. The skin at the site of application was also examined in all remaining dosed groups. | Histopathology was performed on all animals. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, kidney, liver, lung, lymph nodes (mandibular, mediastinal, and mesenteric), mammary gland, ovary, parathyroid gland, pituitary gland, skin, spleen, stomach (forestomach and glandular), thymus, thyroid gland, trachea, and uterus.
Sperm Motility and Vaginal Cytology
None | At the end of the studies, sperm samples were collected from vehicle control, 1.5, 3, and 6 mg/kg core study male rats and vehicle control, 3, 6, and 12 mg/kg male mice for sperm motility evaluations. The following parameters were evaluated: spermatid heads per testis and per gram testis, spermatid counts, and epididymal spermatozoal motility and concentration. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 12 consecutive days prior to the end of the studies from vehicle control, 1.5, 3, and 6 mg/kg core study female rats and vehicle control, 3, 6, and 12 mg/kg female mice for vaginal cytology evaluations. The percentage of time spent in the various estrous cycle stages and the estrous cycle length were evaluated. | None | None

## Statistical Methods

### Calculation and Analysis of Lesion Incidences

The incidences of lesions are presented in Appendixes A, B, C, and D as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test (Gart et al., 1979), a procedure based on the overall proportion of affected animals, was used to determine significance.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed groups and vehicle control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett (1955) and Williams (1971, 1972). Hematology, clinical chemistry, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley (1977) (as modified by Williams, 1986) and Dunn (1964). Jonckheere’s test (Jonckheere, 1954) was used to assess the significance of dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey (1957) were examined by NTP personnel, and implausible values were eliminated from the analysis. Average severity values were analyzed for significance with the Mann-Whitney U test (Hollander and Wolfe, 1973). Because vaginal cytology data are proportions (the proportion of the observation period that an animal was in a given estrous stage), an arcsine transformation was used to bring the data into closer conformance with a normality assumption. Treatment effects were investigated by applying a multivariate analysis of variance (Morrison, 1976) to the transformed data to test for simultaneous equality of measurements across exposure concentrations.

## Quality Assurance Methods

The 3-, 13-, 20- and 27-week studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations (21 CFR, Part 58). In addition, as records from these studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent quality assurance contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Report.

## Genetic Toxicology

### Salmonella typhimurium

#### Mutagenicity Test Protocol

Testing was performed as reported by Zeiger et al. (1992). Dicyclohexylcarbodiimide was sent to the laboratory as a coded aliquot from Radian Corporation (Austin, TX). It was incubated with the Salmonella typhimurium tester strains TA97, TA98, TA100, and TA1535, either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague-Dawley rat or Syrian hamster liver) for 20 minutes at 37° C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following 2 days incubation at 37° C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and five doses of dicyclohexylcarbodiimide. The high dose was limited by toxicity. All trials were repeated at the same or a higher S9 fraction.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive.

#### Rat Bone Marrow Micronucleus Test Protocol

The detailed protocol is described by Witt et al. (1999). Information from the 13-week study with dicyclohexylcarbodiimide was used to select the range of doses in this test. The standard three-injection protocol is described in detail by Shelby et al., 1993. Five male F344/N rats per dose group were injected intraperitoneally (three times at 24-hour intervals) with dicyclohexylcarbodiimide dissolved in corn oil. Vehicle control animals were injected with corn oil alone. The positive control for each trial was cyclophosphamide administered by intraperitoneal injection at a dose of 25 mg/kg. The rats were killed 24 hours after the third injection, and blood smears were prepared from bone barrow cells obtained from femurs. Air-dried smears were fixed in absolute methanol and stained with acridine orange (Tice et al., 1990). Two thousand polychromatic erythrocytes (PCEs) were scored for the frequency of micronucleated cells in two to five rats per dose group. In addition, the percentage of PCEs among the total erythrocyte population was scored for each dose group as a measure of toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group, plus or minus the standard error of the mean. The frequency of micronucleated cells among PCEs was analyzed by a statistical software package that tested for increasing trend over dose groups with a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each dosed group and the control group (ILS, 1990). In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single dosed group is less than or equal to 0.025 divided by the number of dosed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, reproducibility of any effects observed, and the magnitudes of those effects.

#### Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by Witt et al. (1999). At the end of the 13-week study, peripheral blood samples were obtained from male and female B6C3F_1_ mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned at 1,000× magnification using epi-illuminated fluorescence microscopy to determine the frequency of micronuclei in 1,000 normochromatic erthyrocytes (NCEs) in each of 10 mice per dose group per sex. The percentage of PCEs among total erythrocytes was also determined.

The results were tabulated as described for PCEs in the bone marrow micronucleus test protocol. Results of the 13-week study were accepted without repeat tests because additional test data could not be obtained.

#### Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple aliquots of a chemical were tested in the same assay, and different results were obtained among aliquots and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary tables in the Abstract of this Report present a result that represents a scientific judgement of the overall evidence for activity of the chemical in an assay.