# INTRODUCTION

DICYCLOHEXYLCARBODIIMIDE

CAS No. 538-75-0

Chemical Formula: C_13_H_22_N_2_ Molecular Weight: 206.32

Synonyms: Carbodicyclohexylimide; DCC; DCCI; N,N’-methanetetraylbis(cyclohexanamine)

## Chemical and Physical Properties

Dicyclohexylcarbodiimide, a colorless crystalline solid with a heavy sweet odor, is a key chemical of the carbodiimide class of chemicals. Dicyclohexylcarbodiimide has a melting point of 35° to 36° C; boiling point ranges of 98° to 100° C (0.5 mm Hg), 138° to 140° C (2 mm Hg), and 154° to 156° C (11 mm Hg ); and a flash point greater than 110° C (Sax and Lewis 1987; Merck, 1989; Aldrich, 1990). Dicyclohexylcarbodiimide is soluble in organic solvents, moisture sensitive, corrosive to tissue, incompatible with acids and oxidizers, and emits toxic fumes when combusted (Sax and Lewis, 1987; Kuney, 1990).

Dicyclohexylcarbodiimide is available in purities ranging from 99% to 99.5% in quantities up to 1,000 kg (Kuney, 1990; Van, 1990). The main impurities are unreacted isocyanates and polymerized carbodiimides (Chadwick and Cleveland, 1979).

## Production, Use, and Human Exposure

Dicyclohexylcarbodiimide is manufactured by heating cyclohexyl isocyanate. The use of a catalyst accelerates the reaction and makes the production of dicyclohexyl carbodiimide practical. Phospholine oxides are particularly effective catalysts, although simple trialkyl phosphine oxides or triethyl phosphate may also be used. The dimer is not an intermediate in the uncatalyzed reaction; in the presence of a phosphine oxide catalyst, a four-membered ring intermediate is highly probable (Chadwick and Cleveland, 1979). Alternative manufacturing methods have been suggested: 1) N,NN-dicylclohexylthiourea is reacted with cyanuric chloride in dichloromethane to yield an oily product that can be hydrolyzed with sodium hydroxide and heated, producing dicyclohexylcarbodiimide and trithiocyanuric acid (Furumoto, 1971a), or 2) N,NN-dicyclohexylthiourea is treated with dichlorodicyanobenzoquinone in dichloromethane to produce a mixture that can be evaporated and heated in sodium hydroxide to yield dicyclohexylcarbodiimide (Furumoto, 1971b).

Although carbodiimides were discovered in 1873, it was not until the early 1950s that they were used in industry. The reactivity of these compounds with free carboxyl groups made them valuable as stabilizing agents in elastomers, natural rubber, and many types of polyolefins, polyesters, resins, fibers, cellulose esters, and foam materials to protect against deterioration. In 1953, it was discovered that carbodiimides are potent condensing agents for mono- and diesters of phosphoric acid and for the corresponding di- and tetraesters of pyrophosphoric acid. Since then, carbodiimides and dicyclohexylcarbodiimide in particular have been widely used in the synthesis of ortho- and pyrophosphate esters, nucleotides, cyclic phosphates, oligoribonucleotides, polynucleotides, nucleoside-5′-phosphoroamidates, and mixed anhydrides (Azzi et al., 1984). The application of dicyclohexylcarbodiimide-induced formation of an amide bond has been used for many other purposes, among which is the chemical synthesis of peptides. It has been used particularly in the synthesis of polypeptides with high molecular weights from low-molecular weight polypeptides. As the manufacture of polypeptides is a rapidly growing segment of the chemical and pharmaceutical industries, the use of dicyclohexylcarbodiimide is expected to increase. This technique has also been applied in the preparation of gels for affinity chromatography and in a method for the quantitative modification and estimation of carboxylic groups in proteins. In addition, dicyclohexylcarbodiimide is increasingly used in the emerging industry of recombinant DNA as a coupling agent in protein synthesis (Azzi et al., 1984; Hoffman and Adams, 1989). Dicyclohexylcarbodiimide has been used as a coupling agent to produce natural lubricating oils by combining the free carboxyl and amino groups in the oil to neutral amide groups (Azzi et al., 1984), and it has been used to synthesize two protected peptide proteins of scorpion neurotoxin II, steroidal esters of carboxylic derivatives of N,N-bis(2-chloroethyl)aniline, and acylureas (Orlowska et al., 1983; Pairas et al., 1985; Sabatier et al., 1987; Slebioda et al., 1990).

Since the discovery in 1967 that dicyclohexylcarbodiimide inhibits proton-translocating ATPase in mitochondria, it has been widely used in the field of bioenergetics. Studies have used this inhibitory effect on ATPases to determine the structure and function of membrane transport systems and enzyme complexes. These have included proton ATPases in mitochondria, chloroplasts, bacteria, and chromaffin granules (the catecholamine vesicles of the adrenal medulla); Ca^2+^-ATPase of sarcoplasmic reticulum; mitochondrial nicotinamide nucleotide transhydrogenase; cytochrome c oxidase (the terminal electron-transporting enzyme of the respiratory chain of mitochondria and bacteria); and the cytochrome bc_1_ complex of the mitochondrial respiratory chain (Azzi et al., 1984).

Human exposure to dicyclohexylcarbodiimide could occur during the extensive handling of the compound that occurs during the synthesis of peptides and other compounds in the chemical, pharmaceutical, and recombinant DNA industries.

## Absorption, Distribution, Metabolism, and Excretion

The NTP performed absorption, distribution, metabolism, and excretion studies of dicyclohexylcarbodiimide in F344/N rats and B6C3F_1_ mice (Appendix J). When radiolabeled dicyclohexylcarbodiimide was administered intravenously, rats excreted approximately 50% in urine, 20% to 30% in feces, and less than 1% in breath as volatile organics and CO_2_; mice excreted approximately 50% in urine, 25% in feces, and 1% in breath. Following dermal application of radiolabeled dicyclohexylcarbodiimide, rats absorbed approximately 25% of the administered dose, with most of the dose remaining in the skin at the site of application; mice absorbed approximately 30% to 40% of the administered dose and excreted 11% to 22% in urine and 10% to 14% in feces. Seventy-two hours after dermal application of dicyclohexylcarbodiimide, negligible radioactivity was detected in collected tissues of both rats and mice.

## Toxicity

### Experimental Animals

In rats, the oral LD_50_ for dicyclohexylcarbodiimide is 400 mg/kg, the intraperitoneal LD_50_ is 10 mg/kg, and the inhalation LC_50_ is 159 mg/m^3^ per 6 hours; in mice, the LD_50_ by oral and intraperitoneal routes exceeds 800 mg/kg; in guinea pigs, the dermal LD_50_ is 10 mL/kg (NTIS, 2004). Dicyclohexylcarbodiimide has been identified as an irritant and contact sensitizer when topically applied to female B6C3F_1_ mice at a concentration as low as 0.006% (w/v) (Hayes et al., 1998). The contact hypersensitivity of dicyclohexylcarbodiimide may be dependent on haplotype, however, as different responses have been observed in multiple strains of mice (Kato et al., 2002). In response to sensitization at a minimally irritating dose, different mouse strains with different histocompatibility-2 locus (H2) haplotypes (C57BL/6, H2b; DBA/1, H2q; BALB/c, H2d) responded to dicyclohexylcarbodiimide challenge, but some did not (C3H/HeJ, H2k). Both DBA/1 and FVB/N have the same haplotype (H2q) and, thus, FVB/N (H2q) and B6C3F_1_ mice (H2b/k), which carry both responsive (b) and nonresponsive (k) alleles, should also respond to contact sensitization exposure. A mechanistic relationship between mutagenicity, skin sensitization, and carcinogenicity has been proposed (Ashby et al., 1993) based on reactive intermediate metabolites of mutagenic carcinogens adducting both protein (forming hapten) and DNA. However, contact sensitizers that adduct protein through Michael’s substitution reactions to form hapten are not likely carcinogens. In the FVB/N-Tg.AC (v-Ha-ras) mouse used in these studies, tumorigenicity has been attributed to cytotoxicity and not contact sensitization (Albert et al., 1996). The irritancy of dicyclohexylcarbodiimide to the skin of BALB/c mice has been reported to be exacerbated by concurrent stress (Flint et al., 2003).

Bioenergetic studies have indicated that dicyclohexylcarbodiimide is associated with a variety of adverse biological effects, many of which are due to the time-dependent, irreversible inhibitory effect of the chemical on proton translocation in ATPases and enzyme complexes of the respiratory chain. However, it has also been reported that, in the mucosa of the pig intestine, dicyclohexylcarbodiimide inhibits proline-β-naphthylamidase in a reversible and noncompetitive manner, indicating binding at a site other than its substrate binding site (Takahashi and Takahashi, 1990). Dicyclohexylcarbodiimide readily inactivates Escherichia coli BF1-ATPase at 0.05 mM, while the related chemical, diisopropylcarbodiimide, shows almost no inactivation at this concentration (Satre et al., 1979).

The metabolic effects of dicyclohexylcarbodiimide in suspensions of dog nephron segments has been investigated (Tejedor et al., 1987). In this study, dicyclohexylcarbodiimide inhibited a ouabain-insensitive activity responsible for respiration in proximal tubules but not in the thick ascending limbs. However, measurement of cellular ATP, ADP, and AMP demonstrated that dicyclohexylcarbodiimide interfered with phosphorylation but not respiration in aerobic tissues, probably at the functional oxygenase unit of mitochondrial H^+^-ATPase. It was also found that the effect of dicyclohexylcarbodiimide on ATP turnover in papillary connecting ducts may not reflect direct inhibition of a membrane proton pump.

It has been reported that dicyclohexylcarbodiimide elicited a sharp increase in the rate of oxygen consumption in guinea pig peritoneal neutrophils; the respiratory burst consisted of a lag phase during which NADPH oxidase underwent activation and a superoxide-producing phase (Aviram and Aviram, 1983).

Inactivation of hormone receptors in purified rat ovarian plasma membranes by dicyclohexylcarbodiimide has been reported (Azulai and Salomon, 1979). In these studies, preincubation with 0.5 mM dicyclohexylcarbodiimide reduced human chorionic gonadotrophin binding by 50%, completely abolished hormone-sensitive adenylate cyclase (AC) activity stimulated by lutropin, follotropin, or human chorionic gonadotrophin, but did not affect basal AC activity and activity stimulated by sodium fluoride or guanyl-5′-imidodiphosphate.

### Humans

Occupational contact dermatitis to dicyclohexylcarbodiimide has been reported in research laboratory workers since the late 1950s. Zschunke and Folesky (1975) reported about three research laboratory workers with contact dermatitis in 1959 and seven cases of contact dermatitis in pharmaceutical workers in 1975. Subsequent case reports of skin sensitization have since appeared (Simpson, 1979; White and MacDonald, 1979; Davies, 1983; Funfstuck et al., 1986; Lang and Hensel, 1987; Poesen et al., 1995; Vente et al., 1999). Hoffman and Adams (1989) reported two cases of contact allergic dermatitis to dicyclohexylcarbodiimide used in protein synthesis. A 33-year-old research chemist developed severe, blistering dermatitis of the hands, forearms, neck, and face after working with dicyclohexylcarbodiimide while synthesizing a precursor of an experimental drug. Patch testing of dicyclohexylcarbodiimide at 0.1% and 0.05% concentration in petrolatum elicited strong positive reactions. A 29-year-old chemist who had been working for several months with dicyclohexylcarbodiimide developed acute vesiculobullous dermatitis after contact with crystalline dicyclohexylcarbodiimide. Patch testing revealed strong positive reactions to 0.1% and 0.05% dicyclohexylcarbodiimide in acetone.

Dicyclohexylcarbodiimide vapor has been reported to cause four cases of acute chemical ophthalmitis (Changji, 1983). A related alkylcarbodiimide, diisopropylcarbodiimide, has been reported to have caused delayed, temporary blindness following an acute occupational exposure to diisopropylcarbodiimide vapor in a worker who cleaned up a 1 L spill while wearing a respirator, laboratory coat, and impervious gloves. Approximately 12 to 18 hours later, the worker experienced hazy vision followed by mild pain that maximized 34 hours after the exposure. Damage to the outer layer of the cornea resulted in blindness that was restored over a 2-week period (Moyer, 1990). Ellis (1991) noted that this injury resembled mild to moderate mustard gas injury, for which the postulated mechanism of action is alkylation of nucleophilic functional groups of intracellular components, occurring within minutes of exposure and leading to cellular dysfunction and even cell death. This author noted that it is reasonable to assume that all alkylcarbodiimides are capable of functioning as alkylating agents and are therefore potential vesicants and carcinogens.

## Reproductive and Developmental Toxicity

### Experimental Animals

A single oral reproductive study in rats of the related chemical carbodiimide has been reported (RTECS, 1991). In this study, a dose of 2,450 mg carbodiimide/kg body weight caused preimplantation mortality, 1,750 mg/kg caused paternal effects (testes, epididymis, sperm duct, prostate, seminal vesicle, Cowper’s gland, and accessory glands), and 208 mg/kg affected postimplantation mortality and the live birth index. In the same study, 2,600 mg/kg affected the live birth index and growth statistics in newborn rats.

### Humans

No information on the reproductive or developmental toxicity of dicyclohexylcarbodiimide in humans was found in the published literature.

## Carcinogenicity

No information on the carcinogenicity of dicyclohexylcarbodiimide in animals or epidemiology studies or case reports associating dicyclohexylcarbodiimide with a cancer risk in humans were found in the published literature.

## Genetic Toxicity

Witt et al. (1999) described the results of a series of in vivo mutagenicity tests with dicyclohexylcarbodiimide and the related compound diisopropylcarbodiimide. Both chemicals were shown to induce micronuclei in erythrocytes of male and female B6C3F_1_ mice treated by skin painting for a period of 13 weeks, although the response induced by dicyclohexylcarbodiimide was weak. An additional acute bone marrow micronucleus test with dicyclohexylcarbodiimide in male F344/N rats using intraperitoneal injection as the route of administration gave negative results.

A second subchronic micronucleus study was conducted with diisopropylcarbodiimide in male B6C3F_1_ mice, in which the chemical was administered by skin painting for 18 weeks and weekly or biweekly counts of micronucleated polychromatic erythrocytes (PCEs), micronucleated normochromatic erythrocytes, and the percentage of PCEs were obtained (Witt et al., 1999). Results of this study confirmed the activity of diisopropylcarbodiimide that was observed in the 13-week skin painting study. Similar to what was seen with dicyclohexylcarbodiimide, however, results of short-term tests with diisopropylcarbodiimide in both F344/N rats and B6C3F_1_ mice showed no clear evidence of micronucleus induction in bone marrow PCEs.

## Background on Genetically Altered Mice

Mutation and/or deletions of tumor suppressor genes or activation of protooncogenes can disrupt cell function and predispose an animal to cancer. In the current studies, two genetically altered mouse models with either a loss of heterozygosity in a critical cancer gene (Trp53) or a gain of oncogene function (Ha-ras) were used to determine how these animals would respond to dicyclohexylcarbodiimide exposure. These mouse models are susceptible to the rapid development of cancer. The Tg.AC hemizygous and p53 haploinsufficient mice are being evaluated by the National Institute of Environmental Health Sciences (NIEHS) and the NTP as models for identifying chemical toxicity and/or chemical carcinogenic processes (Tennant et al., 1996; Pritchard et al., 2003).

### FVB/N-TgN(v-Ha-ras)Led (Tg.AC) Hemizygous Mouse Model

Tg.AC mice are hemizygous for a mutant V-Ha-ras transgene. The Tg.AC hemizygous mouse (on an FVB/N background) was developed by Leder et al. (1990) by introduction via pronuclear injection of a tripartite transgene, composed of the promoter of the mouse embryonic zeta-globin gene, through the v-Ha-ras coding sequence, with point mutations in codons 12 and 59, and an SV40 polyadenylation sequence. Because the inducible zeta-globin promoter drives the expression of a mutated v-Ha-ras oncogene, the Tg.AC mouse is regarded as a genetically initiated model.

The Tg.AC transgenic mouse model has been evaluated as a reporter phenotype (skin papillomas) in response to either genotoxic or nongenotoxic carcinogens, including tumor promoters (Spalding et al., 1993, 1999; Tennant et al., 1999). With the exception of bone marrow, constitutive expression of the transgene cannot be detected in adult tissues. The transgene is transcriptionally silent until activated by certain treatments including full-thickness wounding, ultraviolet irradiation, or exposure to some chemicals (Cannon et al., 1997; Trempus et al., 1998). The Tg.AC hemizygous mouse develops a high incidence of skin papillomas in response to topical application of 12-O-tetradecanoylphorbol-13-acetate (TPA), and TPA has been used as a positive control in NIEHS Tg.AC mouse studies (Spalding et al., 1993). TPA has been used as a positive control in NIEHS Tg.AC mouse studies to confirm the mice are responsive to carcinogens because it has been found that a subset of Tg.AC mice may revert and become nonresponsive to a tumor promoter (Honchel et al, 2001). Point mutations in the Ha-ras gene are believed to be early events in the induction of skin papillomas and malignancies. Topical application of carcinogens to the shaved dorsal surface of Tg.AC mice induces epidermal squamous cell papillomas or carcinomas, a reporter phenotype that defines the activity of the chemical. The oral route of administration can also generate tumor responses in the skin of Tg.AC mice and lead to squamous cell papillomas and/or carcinomas of the forestomach. To date, the appearance of either spontaneous or induced tumors has been shown to involve transgene expression. However, the mechanism of response by the Tg.AC model to chemical carcinogens is not yet understood.

In NIEHS studies, mice are exposed beginning at 2 months of age for a total of 6 to 9 months. Cutaneous papillomas at various sites have been reported at 10% and 7% incidence in 33-week-old control male and female Tg.AC mice, respectively (Mahler et al., 1998). Cutaneous papillomas occurring at sites such as the lip, pinnae, prepuce, and vulva suggest a possible relationship to grooming and chronic irritation. Up to 32% of Tg.AC homozygous and heterozygous male or female mice can develop odontogenic tumors as early as 33 weeks (Wright et al., 1995; Mahler et al., 1998). A number of different tumor types occur in untreated Tg.AC hemizygous mice at an incidence of greater than 3% including odontogenic tumors, forestomach papillomas, cutaneous papillomas, alveolar-bronchiolar adenomas, salivary gland duct carcinomas, and erythroleukemia (Mahler et al., 1998). In the FVB mouse (the background strain for the Tg.AC hemizygous mouse), alveolar/bronchiolar neoplasms occur at 14 months of age (Mahler et al., 1996).

The Tg.AC hemizygous mouse model was used in the current Report for the studies of dicyclohexylcarbodiimide because this model has been reported to detect both nongenotoxic and genotoxic carcinogens (Spalding et al., 1993; Tennant et al., 1995, 1996; Pritchard et al., 2003).

### B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient Mouse Model

The heterozygous B6.129-Trp53 (N12)^tmlBrd(+/–)^ mouse (on a B6.129S7 background) was developed by Donehower et al. (1992). A null mutation was introduced into one p53 allele by homologous recombination in murine embryonic stem cells. Insertion of a neo cassette resulted in deletion of a 450-base pair gene fragment containing 106 nucleotides of exon 5 and approximately 350 nucleotides of intron 4.

Trp53, a nuclear protein, plays an essential role in the regulation of the cell cycle, specifically in the transition from G_0_ to G_1_, as well as G_2_ to M, and the spindle apparatus. The p53 protein has a short half-life and exists at a very low concentration under normal cell physiological conditions. However, in DNA damaged cells that are able to replicate, p53 is expressed in high amounts with a significant increase in half-life due to posttranslational modification (phosphorylation or acetylation). Mutation in p53 may also increase the protein half-life and alter the functions that may contribute to transformation and development of the malignant phenotype. p53 is a DNA-binding protein containing DNA-binding, oligomerization, and transcription activation domains. Many amino acid residues in different p53 domains may be phosphorylated or acetylated, which may determine specific p53 functions. It is postulated to bind as a tetramer to a p53-binding site and activate expression of downstream genes that inhibit growth and/or invasion or promote apoptosis, functioning as a tumor suppressor. This protein is critical to tumor suppression in humans and rodents. Mutants of p53 that fail to bind the consensus DNA binding site, and hence are unable to function as tumor suppressors, frequently occur in human cancers. Alterations of the Trp53 gene occur not only as somatic mutations in human malignancies, but also as germline mutations in some cancer-prone families with Li-Fraumeni syndrome.

The mouse heterozygous for a p53 null allele (+/–) has only a single functional wild-type p53 allele which provides a target for mutagens. The p53 tumor suppressor gene is one of the most common sites for mutations and gene alterations in human cancer (Harris, 1996a,b,c).

Heterozygous p53^(+/–)^ mice develop normally, and like humans and other mammals, develop cancer (primarily lymphomas or sarcomas) with age, but often with decreased latency.

## Study Rationale and Design

Dicyclohexylcarbodiimide and diisopropylcarbodiimide were nominated by the National Cancer Institute for toxicity and carcinogenicity studies as representatives of the carbodiimide chemical class. The results of the diisopropylcarbodiimide studies were presented in separate Reports (NTP, 2007a,b).

Carbodiimides are known to be irritating to the skin, eyes, and respiratory tract. Despite a lack of adequate carcinogenicity data, dicyclohexylcarbodiimide is widely used in industry as a stabilizing agent, coupling agent, and condensing agent. Because of increasing use of dicyclohexylcarbodiimide in the synthesis of polypeptides in the chemical, pharmaceutical, and recombinant DNA industries, the potential for low-level human exposure has grown. The dermal route of exposure was chosen for the studies in this Report to mimic the primary route of human exposure.

Two of the studies in the current Report were performed in genetically modified mice. These studies in Tg.AC hemizygous and p53 haploinsufficient mouse models were performed as part of the NTP effort to evaluate alternative cancer models that require shorter exposure times, are less expensive to study, and use fewer animals when compared to the traditional 2-year study design.