# APPENDIX J ABSORPTION, DISTRIBUTION, METABOLISM, AND EXCRETION

## Introduction

Dicyclohexylcarbodiimide is a highly reactive compound used widely as a condensing agent in the preparation of peptides and nucleotides and as a stabilizing agent for polymers. Dicyclohexylcarbodiimide is a white crystalline solid with a melting point of 35° C. It is soluble in most organic solvents and reacts with most nucleophilic species including water, alcohols, amines, thiols, carboxylic acids, and phosphates. The potential for human exposure to dicyclohexylcarbodiimide exists during its use in the synthesis of polypeptides in the chemical and pharmaceutical industries, as well as during protein synthesis in the recombinant DNA industry.

Carbodiimides are known to be irritating to the skin, eyes, and respiratory tract. Occupational contact dermatitis due to dicyclohexylcarbodiimide exposure has been reported in laboratory workers since the later 1950s, and dicyclohexylcarbodiimide vapor has been reported to cause acute ophthalmitis. It is believed that dicyclohexylcarbodiimide may function as an alkylating agent and, therefore, is a potential vesicant and/or carcinogen.

As presented elsewhere in this Report, the NTP has conducted 13-week dermal toxicity studies of dicyclohexylcarbodiimide at doses up to 12 mg/kg in F344/N rats and 24 mg/kg in B6C3F_1_ mice. In these studies, the dose application sites were not covered. All of the animals in the highest dose groups for both species died, possibly due to acute central nervous system toxicity. Nonneoplastic lesions including epidermal hyperplasia, inflammation, or necrosis were observed in the skin at the site of application in most of the dosed groups in both species. During 3-week repeated-dose dermal toxicity studies in F344/N rats and B6C3F_1_ mice similarly treated with dicyclohexylcarbodiimide, similar dose-related clinical signs of neurotoxicity were reported.

The carcinogenic potential of dicyclohexylcarbodiimide has been studied by the NTP in Tg.AC hemizygous mice as also presented elsewhere in this Report, using uncovered dermal applications of the chemical for 20 weeks at doses of 0, 0.75, 1.5, 3, 6, or 12 mg/kg. Increased incidences of epidermal hyperplasia and dermal inflammation occurred in the skin at the site of application in groups administered 3 or 6 mg/kg dicyclohexylcarbodiimide, and the chemical was found to have carcinogenic potential in these animals, as squamous cell papilloma of the skin at the site of application occurred in animals dosed with 1.5 mg/kg or greater.

The objectives of the studies described here were to: a) determine the absorption and rates and routes of excretion of radiolabeled compounds following dermal exposure to [^14^C]-dicyclohexylcarbodiimide, b) determine the rates and routes of excretion of radiolabeled compounds following intravenous administration of [^14^C]-dicyclohexylcarbodiimide, c) determine the timecourse of radioactivity in blood following intravenous administration, and d) characterize, to the extent possible, the metabolites of [^14^C]dicyclohexylcarbodiimide in blood, urine, and selected tissues.

## Materials and Methods

Young adult male F344/N rats and B6C3F_1_ mice were obtained from Charles River Laboratories (Raleigh, NC). Animals were quarantined for at least 1 week prior to being used in a study. Animals used for excreta collection were acclimated to the metabolism chambers 1 day prior to dosing. Animals were fed certified Purina Rodent Chow (#5002) and furnished tap water ad libitum. Prior to study initiation, animals within the required weight range were randomized to ensure unbiased choice of study animals. Animals were housed in polycarbonate cages with stainless steel bar lids accommodating pelleted feed and water. Cage sizes were 19” × 10.5” × 8” high for rats, and 11.5” × 7.5” × 5” high for mice. Bedding was either Ab-Sorb-Dri^®^ hardwood chips (Lab Products, Maywood, NJ) or Sani-Chips^®^ (P. J. Murphy Forest Products Corp., Montville, NJ). Room temperature was maintained at 64° to 79° F, and relative humidity ranged from 30% to 70%. Light/darkness was cycled at 12-hour intervals. Animals used for the collection of excreta were housed individually in all-glass, Roth-type metabolism chambers that provided for separate collection of urine, feces, carbon dioxide (CO_2_), and expired volatiles during the collection interval.

Anesthesia of the animals was used to minimize pain or distress. Rats were anesthetized with an intramuscular injection of ketamine:xylazine (7:1, approximately 60 mg/kg or to effect). Mice were anesthetized with an intraperitoneal injection of sodium pentobarbital (60 mg/kg or to effect). Anesthetized rats were euthanized by cutting the diaphragm after final blood collection or by CO_2_ asphyxiation at the end of the study. Anesthetized mice were euthanized by cervical dislocation, cutting the diaphragm, or CO_2_ asphyxiation after final blood collection.

Rats were surgically fitted with indwelling jugular cannulae for serial blood sampling. The cannula design was similar to that of Harms and Ojeda (1974) as modified by McKenna and Bieri (1984). Rats were anesthetized, and access to the right external jugular vein was gained by a ventral incision of approximately 2 cm at the level of the clavicle approximately 0.5 cm from the midline. The vessel was blunt dissected, and the cannula (filled with sterile saline containing 20 IU/mL of sodium heparin) was inserted to a depth of approximately 28 mm. Placement in the atrium was confirmed by patency. The cannula was secured to the vessel and at the site of insertion by sutures to the surrounding musculature and was then exteriorized by passing the distal end subcutaneously around the neck to exit the dorsal surface via a small incision between the scapulae. The ventral incision was closed with sutures, and the distal end of the cannula was coiled and sutured to the base of the neck between the scapulae. Animals were allowed to recover in their metabolism chambers for approximately 24 hours prior to dosing.

Approximately 24 hours prior to dermal dose administration, animals were anesthetized and the fur on their backs was removed with a No. 40 animal clipper (Oster^®^ Professional Products, Milwaukee, WI). The clipped area was washed with soapy water, rinsed with water, dried, and wiped with acetone. The clipped area was not wiped with acetone for the 0.7 and 6.2 mg/kg definitive dermal studies in mice. The clipped area was examined for nicks or breaks in the skin; any animal with broken skin was excluded. A dose application site was inscribed within the clipped area using a permanent felt tip marker for rats (12 cm^2^) and mice (2.8 cm^2^). The animals were placed in individual glass metabolism chambers to recover prior to dosing.

Nonradiolabeled dicyclohexylcarbodiimide (purity 99%) was obtained from Aldrich Chemical Company, Inc. (Milwaukee, WI), in one lot (PG06319KG). The identity of the nonradiolabeled dicyclohexylcarbodiimide was confirmed by nuclear magnetic resonance (NMR) spectroscopy and gas chromatography/mass spectrometry.

Dicyclohexylcarbodiimide, uniformly labeled with carbon-14 in the cyclohexyl ring (2 µCi/µL in hexanes, 11.14 µg/µL, 37.04 mCi/mmol, 10 mCi total), was received from Wizard Laboratories, Inc. (West Sacramento, CA), at a stated radiochemical purity of 98.8% determined by thin layer chromatography. The radiochemical purity of [^14^C]-dicyclohexylcarbodiimide was determined by high performance liquid chromatography (HPLC). The HPLC system consisted of a Waters model 510 pump (Waters Corp., Milford, MA), a Rheodyne model 7125 injector (Rheodyne LLC, Rohnert Park, CA), a Supelcogel^®^ TPR-100 column (15 cm × 0.46 cm) (Supelco, Bellefonte, PA), and a $-Ram radioactivity detector equipped with a 100 µL solid glass scintillator flow cell (IN/US Systems Inc., Tampa, FL). The mobile phase was acetonitrile at a flow rate of 0.75 mL/minute.

Chemical Structure of Dicyclohexylcarbodiimide

*Position of the ^14^C Radiolabel

1,3-Dicyclohexylurea was prepared from dicyclohexylcarbodiimide by acid hydrolysis. A total of 1.04 g of dicyclohexylcarbodiimide (nonradiolabeled dicyclohexylcarbodiimide spiked with 2.6 µCi of [^14^C]-dicyclohexylcarbodiimide) was dissolved in 2.95 mL of acetonitrile, and 25 mL of 0.1 N hydrochloric acid was added drop-wise with stirring. The reaction mixture was heated at reflux overnight, cooled, and neutralized with 1 N sodium hydroxide. The white precipitate was collected using suction filtration and was rinsed with water. The precipitate was dried and transferred to a scintillation vial for storage. Both ^13^C- and ^1^H-NMR spectra (in dimethyl-d_6_ sulfoxide) were obtained to confirm the identity of the product as 1-3-dicyclohexylurea.

To determine the stability of dicyclohexylcarbodiimide in whole blood from rats, 100 µL of a solution of 0.2 mg [^14^C]-dicyclohexylcarbodiimide/mL of propylene glycol was added to 2 mL of blood, mixed, and then incubated at 37° C. Following incubation for approximately 1, 5, or 15 minutes, 1 mL of hexanes was added to each sample. The samples were vortexed, then centrifuged for 12 minutes at approximately 1,500 × g. Weighed aliquots of the hexanes extracts and the pellets (following solubilization) were analyzed by liquid scintillation spectrometry (LSS), and the total radioactivity extracted from blood was calculated. The stability of dicyclohexylcarbodiimide in whole blood from mice was assessed using a procedure similar to that described above for rats. A 10 µL solution of 0.2 mg [^14^C]-dicyclohexylcarbodiimide/mL of propylene glycol was added to 0.25 mL of mouse blood, mixed, and incubated at 37° C for up to 30 minutes. At individual time points, the samples were extracted and analyzed for radiochemical content as described previously.

Intravenous dose formulations contained sufficient quantities of [^14^C]-dicyclohexylcarbodiimide and nonradiolabeled dicyclohexylcarbodiimide dissolved in propylene glycol [containing up to 2% (v:v) ethanol] to deliver doses of 0.3 to 3 mg/kg to rats and 0.4 to 0.6 mg/kg to mice in a dose volume of 1 to 2.5 mL/kg. Individual dose formulations were prepared the day prior to administration and stored at approximately −20° C.

Dermal dose formulations contained sufficient quantities of [^14^C]-labeled and nonlabeled dicyclohexylcarbodiimide dissolved in hexanes to deliver doses of 0.3 to 3.1 mg/kg (approximately 0.005 to 0.4 mg/cm^2^) to rats and 0.7 to 6.2 mg/kg (approximately 0.005 to 0.05 mg/cm^2^) to mice in a dose volume of approximately 1.5 to 5.0 mL/kg.

To determine the rate of sublimation of dicyclohexylcarbodiimide, a solution of [^14^C]-dicyclohexylcarbodiimide in hexanes, equivalent to a dermal dose formulation, was applied to the internal base of a 20 mL glass scintillation vial. The vial was fitted with a Teflon^®^ septum cap, and a 1-dram glass vial was filled with dry ice and inserted into the scintillation vial below the septum. The base of the scintillation vial was heated in a water bath at approximately 30° to 32° C. After warming for approximately 3 hours, the apparatus was quickly disassembled. The scintillation vial was filled with 2 mL of ethanol and 12 mL of Ultima Gold^TM^ (PerkinElmer, Inc., Boston, MA) scintillation fluor. The 1-dram vial and the Teflon^®^ septum were placed into separate scintillation vials that were also filled with ethanol and Ultima Gold^TM^, and all of the samples were analyzed by LSS.

To determine the extraction efficiency of dicyclohexylcarbodiimide from the charcoal cover used at the site of dermal administration, a solution of [^14^C]-dicyclohexylcarbodiimide in hexanes (approximately 25 µL), equivalent to a dermal dose formulation, was applied to three pieces of charcoal-impregnated filter similar in size to the appliance covers used for mouse dermal experiments. After approximately 20 minutes, each filter was cut into four pieces and oxidized using a Packard Model 306C Oxidizer (Packard Instrument Co., Inc., Downers Grove, IL). ^14^CO_2_ was trapped using Carbosorb^TM^ (PerkinElmer, Inc.) and analyzed by LSS using PermaFluor^TM^ (PerkinElmer, Inc.) as the scintillation cocktail.

For intravenous administration, the dose formulation was mixed by vortexing and the dosing solution was drawn into a glass syringe (1 mL for rats, 250 µL for mice) equipped with a Teflon^®^-tipped plunger (Hamilton Co., Reno, NV) and an appropriately sized needle. Prior to weighing the filled dosing apparatus, excess dose formulation was wiped from the needle. Intravenous dosing of rats was conducted via an indwelling jugular cannula; for mice, the doses were injected into a lateral tail vein. The dose per animal (µCi) was calculated as the difference in the weight of the syringe/needle filled (S_B_) and empty (S_A_) multiplied by the concentration of ^14^C in the dosing formulation (A_D_) minus the ^14^C removed from the needle wipe after dosing (NW) as shown:

[ μ Ci / animal = ( S_B_ − S_A_ ) A_D_ − NW ]

For dermal application in rats, protective appliances used to cover the dose application site were prepared from 6.5 cm × 6.5 cm × 1 cm (length × width × thickness) sections of Reston^®^ self-adhesive foam pads (3M Company, St. Paul, MN). A 4 cm × 4 cm window was cut in the center of each foam section creating a frame. Rubber cement was then applied to the nonadhesive side of one frame and attached to the adhesive side of a second frame (total thickness approximately 2 cm). Additional rubber cement was spread over the nonadhesive side of the double-thickness appliance. At least 24 hours later, strips of double-sided carpet tape (approximately 6 mm wide) were attached to the top (nonadhesive side) of the frame so that no gaps in the tape were present.

Prior to dosing each rat, the skin at the dose application site was reexamined for breaks in the skin. If none were found, a protective appliance was attached to the back of each rat with Hollister^®^ medical adhesive (Hollister, Inc., Libertyville, IL) so that the inside edge of the appliance was approximately 0.5 cm outside of the area where the dose was to be applied. The appliance was secured to the animal by firmly grasping the appliance and underlying skin between the thumb and fingers and gently squeezing. The dose formulations were vortexed before being drawn into the dosing apparatus that consisted of a ball-tipped needle attached to a 500 µL glass syringe. The syringe was filled to the appropriate mark (300 to 360 µL); excess dose formulation was removed from the outside of the needle with a Kimwipe^®^, and the filled apparatus was weighed. The dose was applied to the premarked area of the rat’s back; the syringe tip was wiped with a Kimwipe^®^, and the apparatus reweighed. The Kimwipe^®^ was placed into a scintillation vial containing 2 mL of ethanol and analyzed by LSS after the addition of scintillation cocktail. After dosing, a piece of 50/50 polyester/cotton sheeting was affixed to the appliance frame using carpet tape strips, and a metal appliance shield was taped onto the animal’s back using Elastoplast^®^ (BSN-JOBST, Inc., Charlotte, NC) adhesive bandage prior to returning the rat to its cage.

For dermal studies in mice, the dose formulation was vortexed, drawn into a 50 µL Hamilton syringe, the excess was wiped off the apparatus, the apparatus was weighed, and the formulation was applied to the premarked dose application site. After dosing, the apparatus was wiped again with a Kimwipe^®^ and reweighed. The Kimwipe^®^ was placed into a scintillation vial containing approximately 2 mL ethanol and analyzed by LSS after the addition of scintillation cocktail. After dosing, a nonocclusive protective appliance was glued over the dose application site using Duro Quick Gel^®^ (Loctite Corporation, Cleveland, OH). For high dose dermal studies, the protective appliance was a wire mesh tissue capsule (Shandon Lipshaw, Inc., Pittsburgh, PA). A metal protective shield was also placed over the capsule and attached to the animal using Duro Quick Gel^®^ and Elastoplast^®^ adhesive bandage.

The dermal doses for rats and mice (in µCi) were calculated using the formula described above for the intravenous injection studies in rats and mice.

Urine and feces were collected separately into containers cooled with dry ice. Urine was collected 0, 8, 24, 48, and 72 hours after dosing except for the 0.3 mg/kg pilot intravenous study in rats and the tissue distribution study in mice. Urine collection flasks were also rinsed with methanol; the methanol rinses were analyzed separately. At sacrifice, urine was collected directly from the bladder and added to the last urine collection. Feces were collected once daily. Urine and feces samples were stored in the dark at approximately −20° C until analyzed. An additional cage rinse using hexanes was performed for dermal studies in mice in an effort to recover sublimed dicyclohexylcarbodiimide.

Exhaled volatile organics and CO_2_ were collected during the dermal and intravenous studies in rats and mice. Radiolabeled components in breath were collected by passing air sequentially through the metabolism cage (flow rate=200 to 550 mL/minute), through two cold traps, each containing approximately 60 mL of ethanol, and through a series of two traps each containing approximately 500 mL of 1 N NaOH. The first cold trap was maintained at 4° C using an ice/water bath, and the second was maintained at −60° C using an isopropanol/dry ice bath. The traps were analyzed at 0 hours and changed at 6, 24, 48, and 72 hours for rat studies and at 8, 24, 48, and 72 hours for mouse studies. For some of the dermal studies in mice, in addition to the traps mentioned above, the radiolabeled components in breath were also collected by passing air from the metabolism cage through a charcoal sorbent tube (SKC, Inc., Eighty Four, PA). The charcoal trap was located between the cryogenic and CO_2_ traps and was changed at 4, 8, 24, 48, and 72 hours.

Serial blood collections (approximately 300 µL) were taken at multiple times postdosing. Serial blood samples were collected into heparinized, disposable 1 mL glass syringes (Glaspak^TM^, Becton, Dickinson and Company, Franklin Lakes, NJ). For all studies, blood was collected at sacrifice by cardiac puncture using a heparinized, disposable 10 mL glass syringe for rats and a 1 mL glass syringe for mice. After aliquots were taken for LSS analysis, a 1 mL aliquot of hexanes was added to each of the blood collections. The samples were vortexed and centrifuged for 5 to 10 minutes. The pellet was frozen using a dry ice/acetone bath, and the hexanes layer was transferred to a tared 1/2 dram vial.

At the termination of the dermal studies in rats (72 hours after dose application), the animals were anesthetized and the metal appliance shield was removed and swiped for radioactivity. The polyester/cotton fabric cover was then removed from the foam appliance and placed into a scintillation vial containing 2 mL of ethanol. The dose application site was washed with cotton gauzes soaked with soapy water (approximately 30 mL Liquid Ivory/L). The skin was rinsed with cotton gauzes soaked with water and dried. Each gauze was placed in a separate 20 mL scintillation vial containing 2 mL of water. With the protective appliance still attached, the dose application site was removed from the rat by blunt dissection. Care was taken not to remove any muscle or adipose from under the skin. The excised skin was placed into a Nalgene^®^ bottle containing approximately 60 mL of 2 N ethanolic sodium hydroxide. The appliance was cut into 16 pieces, and each piece was placed into a separate 20 mL scintillation vial containing 2 mL of ethanol. The shield swipes, dose application site wash gauzes, and the appliance pieces were analyzed by LSS.

For the dermal studies in mice, the animals were anesthetized and the dose application site (appliance intact) and surrounding skin were carefully removed by blunt dissection. The charcoal-impregnated filter was removed from the wire mesh tissue capsule. This filter was cut into four pieces and placed into separate scintillation vials to be oxidized. The skin was then excised and attached to a glass funnel with the metal appliance intact. The metal tissue capsule and the skin were rinsed with hexanes and the rinses collected. The metal appliance was then removed from the skin and placed in a jar containing approximately 40 mL of hexanes and 20 mL of acetone. The dose application site was washed with gauzes soaked with hexanes, soapy water, and water. The rinses and gauzes were analyzed by LSS. The excised skin was digested in approximately 10 mL of 2 N ethanolic sodium hydroxide.

Samples of adipose, muscle, skin, kidney, liver, lung, spleen, heart, testes, bladder, and brain were excised from the animals and assayed for radiochemical content. For the intravenous studies in rats, the jugular vein was also excised and assayed for radiochemical content. For the 6 mg/kg intravenous study, the entire brain, heart, kidney, liver, and lung were excised from the animals and stored frozen. Carcasses were digested in 2 N ethanolic sodium hydroxide using approximately 500 mL for each rat and 75 mL for each mouse. For the intravenous studies, the tails were removed from all animals at sacrifice and digested in an appropriate volume of 2 N ethanolic sodium hydroxide.

All samples were assayed for total radioactivity by LSS either after dissolution in scintillation cocktail or following digestion in an organic tissue solubilizer or 2 N ethanolic sodium hydroxide. Darkened samples were neutralized and bleached (perchloric acid/hydrogen peroxide) before analysis. After the addition of scintillation cocktail, samples containing bases were placed in the dark for approximately 6 hours prior to analysis to minimize nonspecific chemiluminescence. Samples were assayed for ^14^C in a Packard Model 1900TR scintillation spectrometer (Packard Instrument Co., Inc.), which was checked monthly for counting efficiency and calibrated for quench correction using the external standard method.

For pharmacokinetic analysis, a standard noncompartmental model number 21 (WinNonlin^®^ Version 1.5, Scientific Consulting, Inc., Cary, NC) was used to analyze the concentration of total radioactivity in blood versus time for the 0.3 mg/kg intravenous study in rats and to calculate the elimination half-life (t_½_) of dicyclohexylcarbodiimide.

## Results

The radiochemical purity of lot PG06319KG of [^14^C]-dicyclohexylcarbodiimide was determined to be approximately 96%, and it contained an impurity (approximately 3%) with the same retention time as 1,3-dicyclohexylurea. The identity of a synthetic standard of 1,3-dicyclohexylurea was confirmed by carbon-13 and proton NMR spectroscopy using DMSO-d_6_ as the solvent; both spectra were in agreement with the literature spectra (Aldrich, 1993) for this compound, with slight differences due to the solvent.

[^14^C]-Dicyclohexylcarbodiimide was stable for up to 73 hours in ethanol when stored at room temperature, with approximately 93% [^14^C]-dicyclohexylcarbodiimide and 6% [^14^C]-1,3-dicyclohexylurea being measured at this timepoint. [^14^C]-Dicyclohexylcarbodiimide was stable for up to 96 hours in propylene glycol; at analysis, 83% to 90% of the radioactivity was associated with [^14^C]-dicyclohexylcarbodiimide and 9% to 15% was associated with [^14^C]-1,3-dicyclohexylurea. Charcoal-impregnated filters retained approximately 90.9% of a representative radiolabeled dose.

To check the sublimation properties of the chemical, a representative dose of [^14^C]-dicyclohexylcarbodiimide was applied to a glass surface warmed to a near physiologic temperature for 3 hours; approximately 26.3% of the radiolabel sublimed, with an overall recovery of 99.6% of the applied dose.

When rat whole blood samples were spiked with [^14^C]-dicyclohexylcarbodiimide in propylene glycol at 37° C and extracted almost immediately with hexanes, approximately 87% of the radiolabel was recovered. HPLC analysis indicated that 92% of the radiolabel was [^14^C]-dicyclohexylcarbodiimide and 5% was [^14^C]-1,3-dicyclohexylurea. When mouse whole blood samples were spiked with [^14^C]-dicyclohexylcarbodiimide in propylene glycol and incubated for 1 minute at 37° C, only 50% of the radiolabel was extracted by hexanes; extraction efficiency dropped below 40% when samples were incubated for 30 minutes before extraction.

[^14^C]-Dicyclohexylcarbodiimide was not stable in rat plasma samples; recovered radiolabel consisted of 76.9% [^14^C]-dicyclohexylcarbodiimide and 20.3% [^14^C]-1,3-dicyclohexylurea for samples containing hexanes, and 61.0% [^14^C]-dicyclohexylcarbodiimide and 36.3% [^14^C]-1,3-dicyclohexylurea when samples were dried under nitrogen. HPLC analysis indicated that the process of drying the hexanes off the samples may have increased the production of [^14^C]-1,3-dicyclohexylurea.

### Intravenous Studies

#### Rats

Male F344/N rats received single intravenous injections of 0.3 (two studies) or 3 mg [^14^C]-dicyclohexylcarbodiimide/kg body weight (approximately 12.1 µCi/animal); after 72 hours, one of the groups received an additional 5.9 mg/kg (13.1 µCi/animal). For all dose groups, 52% to 54% of the administered radioactivity was excreted in urine and 20% to 30% in feces through 48 hours after administration (Table J1). Minimal amounts of radioactivity were excreted (<0.2%) in breath as volatile organics or CO_2_ in rats administered 0.3 mg/kg. Analysis to determine the timecourse of [^14^C]-dicyclohexylcarbodiimide in the blood of rats given a single intravenous injection of 0.3 mg/kg showed a gradual decrease in dicyclohexylcarbodiimide equivalents through 48 hours after administration (Table J2). The elimination half-life of total radioactivity (i.e., parent compound and/or degradation products and metabolites) in blood was determined to be approximately 8.7 hours. In both 0.3 mg/kg intravenous injection studies, less than 0.01% of the radioactivity in blood was extracted with hexanes. Analyses of tissue concentrations of dicyclohexylcarbodiimide equivalents 48 or 72 hours after dosing indicated that brain, heart, kidney, liver, lung, jugular vein, spleen, and adipose had tissue:blood ratios greater than 10 (Table J3). For the three single-dose intravenous studies in rats, the average total recoveries of radiolabel were 88.8%, 89.2%, and 98.9% (Tables J1 and J3).

#### Mice

Seventy-two hours after a single intravenous injection of 0.6 mg/kg (2.5 µCi/animal), male B6C3F_1_ mice excreted approximately 50% of the radioactivity in urine, 25% in feces, and 0.2% and 0.5% as volatile organic compounds and CO_2_ in breath, respectively (Table J4). Approximately 75% of the total dose was excreted within 72 hours of dosing. Tissue analysis indicated tissue:blood ratios greater than 10 for dicyclohexylcarbodiimide equivalents in adipose and heart, and approximately 2% and 6% of the administered radiolabel was detected in the carcass and tail, respectively (Table J5). The mean total recovery of radioactivity was approximately 92% (Tables J4 and J5).

A timecourse study of total radiolabel in the blood of mice following a single intravenous injection of 0.4 mg/kg (1.57 µCi/animal) indicated that approximately 11% of the administered dose was in blood 1 minute after dosing, and the mean concentration of dicyclohexylcarbodiimide equivalents steadily decreased over 48 hours until less than 1% remained in blood (Table J6). Variability in concentration at each timepoint (due to each sample being drawn from a separate animal) made pharmacokinetic analysis impossible.

### Dermal Studies

#### Rats

As shown in Tables J7 and J8, 72 hours after male F344/N rats were administered a single dermal dose of 0.3 or 3.1 mg/kg, approximately 6% or 2.9% of the radioactivity was excreted in urine, respectively; fecal excretion was 0.7% or 0.5%, respectively. For both dose groups, approximately 1% of the administered radioactivity was excreted as exhaled volatile organics. Tissue analysis indicated that 16% or 19% of the radioactivity remained in the application site skin of rats dosed with 0.3 or 3.1 mg/kg, respectively, and less than 2% or 1% were detected in the residual carcasses of the two groups, respectively. Total dermal absorption was approximately 25% of the administered dose in both studies. Although the concentrations of radiolabel in collected tissues and the residual carcass were low in both dosed groups of rats, the heart, kidney, and liver had tissue:blood ratios of dicyclohexylcarbodiimide equivalents greater than 10 (Table J9).

#### Mice

Seventy-two hours after male B6C3F_1_ mice were administered a single dose of 0.7 mg/kg (2.9 µCi/animal; 0.005 mg/cm^2^), the animals had excreted 11% of the applied radioactivity in urine and 14% in feces, with less than 1% of the radioactivity excreted as volatile organics and CO_2_ in breath (Table J10); approximately 2% of the radioactivity remained in the application site skin, 1.5% in collected tissues, and less than 1% in the residual carcass (Table J11). Approximately 30% of the dose was absorbed during the 72-hour study; the average total recovery was 89% of the administered dose and this included 59% of the dose that was unabsorbed. Although tissue absorption of [^14^C]-dicyclohexylcarbodiimide was low in this study, a tissue:blood ratio of dicyclohexylcarbodiimide equivalents of approximately 22 was found in the liver (Table J12).

Seventy-two hours after male B6C3F_1_ mice were administered a single dermal dose of 6.2 mg/kg (25.5 µCi/animal; 0.05 mg/cm^2^), the animals had excreted approximately 22% of the radioactivity in urine, 10% in feces, and less than 2% as volatile organics and CO_2_ (Table J10); approximately 3% of the radioactivity remained in the application site skin, 4.5% in collected tissues, and essentially none was detected in the residual carcass (Table J11). Approximately 41% of the dose was absorbed during the 72-hour study; the average total recovery was 84% of the administered dose and this included 43% of the dose that was unabsorbed.

## Discussion

Dose formulations of [^14^C]-dicyclohexylcarbodiimide in 100% propylene glycol and hexanes were found to be appropriately stable for dose administration and subsequent analysis. Dicyclohexylcarbodiimide has considerable volatility and sublimes at room temperature. Because the dermal applications utilized a nonocclusive appliance to protect from oral ingestion of the applied dose and contamination of the excreta by sloughed skin, it was necessary to implement procedures for recovering the sublimed dose. These procedures included exhaustive cleaning of the metabolism cage and use of activated charcoal appliance covers. Several in vitro experiments were performed to assess the stability of [^14^C]-dicyclohexylcarbodiimide in whole blood and to determine the recovery of radiolabel from whole blood extracted with hexanes. When rat and mouse whole blood samples were spiked with [^14^C]-dicyclohexylcarbodiimide in propylene glycol and extracted, extraction efficiencies dropped rapidly as dicyclohexylcarbodiimide reacted to form solvent-insoluble products.

For the intravenous studies in male F344/N rats, the doses were administered through an indwelling jugular cannula. The rates and routes of excretion of [^14^C]-dicyclohexylcarbodiimide were studied after single intravenous doses of 0.3 or 3 mg/kg. For both of these doses in rats, approximately 54% of the administered radioactivity was excreted in urine and 20% to 30% in feces through 48 hours postdosing. For 0.3 mg/kg rats, minimal amounts (<0.2%) of radioactivity were excreted either as volatile organics or CO_2_. The timecourse of dicyclohexylcarbodiimide equivalents in blood following a single 0.3 mg/kg intravenous dose showed a gradual decrease throughout the 48-hour study. Less than 0.01% of the radioactivity in blood was extractable with hexanes, which suggests that blood radioactivity is associated with metabolites or reaction products of dicyclohexylcarbodiimide rather than dicyclohexylcarbodiimide itself. Pharmacokinetic analysis of the concentration of total radiolabel in blood versus time showed that the elimination half-life of [^14^C]-dicyclohexylcarbodiimide is 8.7 hours.

For the intravenous studies in male B6C3F_1_ mice, doses were administered through a lateral tail vein. The rates and routes of excretion of [^14^C]-dicyclohexylcarbodiimide were studied after a single intravenous dose of 0.6 mg/kg. Approximately 50% of the radioactivity was excreted in urine and 25% in feces by 72 hours after dosing. Approximately 0.5% of the radioactivity was excreted as CO_2_ and 0.2% as volatile organics in breath. This amount is less than that recovered in the volatile organic traps during the dermal study (approximately 1.5%) and suggests that the traps used in the dermal study may have trapped a small amount of the sublimed dose. A mean total of approximately 75% of the applied radioactivity was excreted during the 72-hour study, and approximately 92% of the dosed radioactivity was recovered; because similar results were obtained from the intravenous injection studies in rats, this suggests that the rates of excretion in rats and mice are similar. Adipose, heart, and liver had elevated tissue:blood ratios of dicyclohexylcarbodiimide equivalents; unlike the dermal study in mice, the skin:blood ratio was not elevated. Approximately 2% of the radiolabel remained in the residual carcass, while the tail contained approximately 6%, suggesting that [^14^C]-dicyclohexylcarbodiimide may chemically react at or near the site of injection and not be entirely systemically available. This was also demonstrated by the timecourse of [^14^C]-dicyclohexylcarbodiimide-derived radioactivity in blood; 1 minute after a single intravenous administration of 0.4 mg/kg, approximately 11% of the administered radiolabel was measured in the blood, and the percentage steadily decreased at each subsequent timepoint until less than 1% remained after 48 hours.

In studies not reported here, urine from intravenously dosed F344/N rats was analyzed by HPLC in an effort to develop a chromatographic method for the separation of what appeared to be numerous metabolites. Chromatographic resolution of all urinary metabolites was not achieved. However, the number of metabolites detected raised a question of whether [^14^C]-dicyclohexylcarbodiimide had reacted with various endogenous materials to form radiolabeled components or simply formed [^14^C]-1,3-dicyclohexylurea, which was excreted in the urine and chromatographed in close association with normal urine components. Samples of urine from an intravenous study were subjected to ultrafiltration; approximately 79% of the recovered radiolabel was in the filtrate. This result suggests that the urinary metabolites of dicyclohexylcarbodiimide are small molecules.

An experiment to test charcoal as a potential dermal appliance trap for volatilized [^14^C]-dicyclohexylcarbodiimide demonstrated that approximately 91% of an applied radiolabeled dose could be recovered from a charcoal-impregnated filter by combustion. Single-dose dermal administration studies were conducted in male F344/N rats at 0.3 (0.005 mg/cm^2^) and 3.1 mg/kg (0.05 mg/cm^2^). The dose application sites were covered by nonocclusive appliances in these studies, and the rates and routes of excretion were found to be similar through 72 hours following application; 3.1 mg/kg rats excreted approximately 3% of administered radioactivity in urine and less than 1% in feces, and 0.3 mg/kg rats excreted approximately 6% of the applied radioactivity in urine and a minimal amount in feces over the same time interval. For both groups, approximately 1% of the applied radioactivity was recovered as volatile organic compounds in breath. For 3.1 mg/kg rats, approximately 19% of the applied radioactivity remained in the application site skin and less than 1% remained in the residual carcass; for 0.3 mg/kg rats, approximately 16% of the radioactivity remained in the application site skin and approximately 2% was found in the residual carcass. Total dermal absorption of dicyclohexylcarbodiimide was similar at the two doses. Although only a small percentage of the dose was found in collected tissues and the residual carcass of the rats at 72 hours, several tissues (heart, kidney, and liver) had elevated tissue:blood ratios of dicyclohexylcarbodiimide equivalents, but these ratios are not biologically relevant due to the low amount found in tissues and blood.

Single-dose dermal administration studies were conducted in male B6C3F_1_ mice at 0.7 mg/kg (0.005 mg/cm^2^ and 6.2 mg/kg (0.05 mg/cm^2^) to determine the dermal absorption of [^14^C]-dicyclohexylcarbodiimide, the rates and routes of excretion, and the terminal body burden. As in the dermal studies in rats, the dose application sites were covered by nonocclusive protective appliances, and the rates and routes of excretion were similar in the two dose groups 72 hours after administration; 6.2 mg/kg mice excreted approximately 22% of the administered radioactivity in urine and 10% in feces, and 0.7 mg/kg mice excreted approximately 11% of the applied radioactivity in urine and 14% in feces. In both dose groups, less than 2% of the applied radioactivity was excreted as volatile organics and CO_2_ in breath. The application site skin contained approximately 2% to 3% of each dose, and the residual carcass contained less than 1%. Approximately 41% of the 6.2 mg/kg dose and 30% of the 0.7 mg/kg dose were absorbed by mice during the 72-hour exposures. The mean total recoveries of administered radioactivity were approximately 84% and 89% for the 6.2 and 0.6 mg/kg groups, respectively. Only small percentages of the applied doses were found in collected tissues and the residual carcass; however, elevated tissue:blood ratios of dicyclohexylcarbodiimide equivalents were observed for adipose, skin, heart, liver, and kidney for 6.2 mg/kg mice and liver only for 0.7 mg/kg mice. Since so little radioactivity was present in the blood, the tissue:blood ratios have limited biological relevance.

## REFERENCES

The Aldrich Library of ^13^C and ^1^H FT-NMR Spectra (1993). 1st ed., p. 1310(B). Aldrich Chemical Co., Inc., Milwaukee, WI.
Harms, P.J., and Ojeda, S.R. (1974). A rapid and simple procedure for chronic cannulation of the rat jugular vein. J. Appl. Physiol. 36, 391–392.4814312
McKenna, M.C., and Bieri, J.G. (1984). Multilayer cannula for long-term infusion of unrestrained rats. Lab. Anim. Sci. 34, 308–310.6748611

TABLE J1 Cumulative Excretion of Radioactivity by Male F344/N Rats After a Single Intravenous Injection of [^14^C]-Dicyclohexylcarbodiimide

End of Collection Period (hours) | Urine^a^ | Cage Rinse | Feces | Volatile Organics | Exhaled CO_2_ | Total
| 0.3 mg/kg ^b^
6 | —^c^ | — | — | 0.04 ± 0.02 | 0.08 ± 0.01 | 0.12 ± 0.03
8 | 31.2 ± 7.2 | — | — | 0.04 ± 0.02 | 0.08 ± 0.01 | 31.3 ± 7.1
24 | 49.5 ± 4.2 | — | 16.5 ± 1.5 | 0.08 ± 0.03 | 0.14 ± 0.02 | 66.2 ± 5.2
48 | 52.4 ± 4.5 | — | 20.5 ± 0.9 | 0.11 ± 0.05 | 0.16 ± 0.02 | 73.1 ± 5.4
72 | 53.7 ± 4.7 | 0.4 ± 0.2 | 21.6 ± 1.4 | 0.12 ± 0.05 | 0.17 ± 0.02 | 75.9 ± 6.1
| 0.3 mg/kg ^b^
8 | 33.1 ± 3.8 | — | — | — | — | 33.1 ± 3.8
24 | 51.7 ± 2.3 | — | 15.7 ± 2.5 | — | — | 67.4 ± 3.8
48 | 54.3 ± 2.4 | 1.0 ± 0.3 | 20.0 ± 3.9 | — | — | 75.6 ± 3.9
| 3 mg/kg ^d^
8 | 34.5 ± 2.2 | — | — | — | — | 34.5 ± 2.2
24 | 51.2 ± 1.9 | — | 24.8 ± 12.9 | — | — | 76.8 ± 11.5
48 | 53.9 ± 1.6 | — | 30.3 ± 12.1 | — | — | 84.3 ± 10.8
72 | 55.0 ± 1.7 | 0.4 ± 0.2^e^ | 31.4 ± 12.0 | — | — | 86.4 ± 10.7^e^

a Urine analysis includes the methanol rinse of the urine flask for all samples except the 72-hour sample after the 3 mg/kg dose; for this sample, the methanol rinse is included in the total only.

b Data are presented as cumulative percentage of the dose (mean ± standard deviation) for five rats.

c No collection was scheduled for this time interval

d Data are presented as cumulative percentage of the dose (mean ± standard deviation) for six rats.

e n=3

TABLE J2 Concentrations of Radiolabel in Blood of Male F344/N Rats After a Single Intravenous Injection of 0.3 mg/kg [^14^C]-Dicyclohexylcarbodiimide

Time After Dosing (hours) | Dicyclohexylcarbodiimide Equivalents in Blood (ng-Eq/g Blood)
Time After Dosing (hours) | Rat 1 | Rat 2 | Rat 3 | Rat 4 | Rat 5 | Mean^a^
IAD | 145 | 153 | 154 | 148 | 168 | 154 ± 8.8
0.08 | 141 | 149 | 155 | 135 | 156 | 147 ± 9.0
0.17 | 135 | 138 | 151 | 151 | 142 | 143 ± 7.4
0.33 | 130 | 138 | 151 | 153 | 135 | 141 ± 10.1
0.67 | 122 | 124 | 128 | 151 | 132 | 132 ± 11.8
1 | 110 | 109 | 118 | 118 | 112 | 113 ± 4.1
2 | 95.2 | 89.4 | 94.3 | 105 | 95.4 | 95.8 ± 5.6
4 | 68.2 | 77.2 | 83.2 | 108 | 77.7 | 82.9 ± 15.1
8 | 50.7 | 52.8 | 48.1 | 74.6 | 53.9 | 56.0 ± 10.6
24 | 25.9 | 16.8 | 24.6 | 47.8 | 22.6 | 27.5 ± 11.8
48 | 2.1 | 2.7 | 2.6 | 2.4 | 2.7 | 2.5 ± 0.3

IAD=Sample acquired immediately after dosing, approximately 2 to 4 minutes.

a Data are presented as mean ± standard deviation.

TABLE J3 Tissue Distribution of Radiolabel in Male F344/N Rats 48 or 72 Hours After a Single Intravenous Injection of [^14^C]-Dicyclohexylcarbodiimide

Tissue^a^ | Dicyclohexylcarbodiimide Equivalents in Tissue (ng-Eq/g Tissue) | Tissue:Blood Ratio | Dose in Total Tissue (%)^b^
| 0.3 mg/kg^c^ (72 hours)
Adipose | 221.0 ± 56.1 | 82.1 ± 23.4 | 5.2 ± 1.4
Bladder | 27.3 ± 5.7 | 10.1 ± 1.6 | 0.004 ± 0.001
Blood | 2.7 ± 0.2 | Unity | 0.047 ± 0.003
Brain | 71.6 ± 33.4 | 26.7 ± 12.9 | 0.2 ± 0.1
Heart | 186.0 ± 89.2 | 69.3 ± 34.2 | 0.20 ± 0.08
Jugular Vein | 45.2 ± 17.5 | 16.9 ± 7.1 | 0.015 ± 0.003
Kidney | 109.0 ± 16.0 | 40.3 ± 3.4 | 0.30 ± 0.03
Liver | 23.4 ± 2.5 | 8.6 ± 0.5 | 0.321 ± 0.006
Lung | 44.3 ± 27.7 | 16.6 ± 10.7 | 0.06 ± 0.03
Muscle | 26.8 ± 7.5 | 9.9 ± 2.4 | 4.3 ± 1.2
Skin | 21.5 ± 5.7 | 8.0 ± 2.0 | 1.2 ± 0.3
Spleen | 34.4 ± 9.0 | 12.6 ± 2.6 | 0.03 ± 0.01
Testes | 12.4 ± 1.8 | 4.6 ± 0.7 | 0.05 ± 0.01
Carcass | NA | NA | 0.83 ± 1.1
| 0.3 mg/kg^c^ (48 hours)
Adipose | 221.0 ± 69.9 | 90.5 ± 33.5 | 5.1 ± 1.6
Bladder | 23.7 ± 7.7 | 9.7 ± 3.6 | 0.004 ± 0.002
Blood | 2.5 ± 0.2 | Unity | 0.043 ± 0.004
Brain | 66.9 ± 4.0 | 26.9 ± 1.5 | 0.17 ± 0.01
Heart | 157.0 ± 18.1 | 63.5 ± 11.3 | 0.17 ± 0.01
Jugular Vein | 55.9 ± 9.7 | 22.9 ± 6.5 | 0.018 ± 0.004
Kidney | 143.0 ± 5.6 | 58.0 ± 6.9 | 0.36 ± 0.03
Liver | 35.5 ± 1.4 | 14.3 ± 1.5 | 0.45 ± 0.03
Lung | 37.6 ± 2.9 | 15.2 ± 1.6 | 0.046 ± 0.003
Muscle | 30.4 ± 3.1 | 12.2 ± 0.7 | 4.8 ± 0.5
Skin | 26.3 ± 4.3 | 10.6 ± 2.1 | 1.5 ± 0.3
Spleen | 44.4 ± 5.9 | 17.8 ± 1.6 | 0.04 ± 0.01
Testes | 13.8 ± 0.6 | 5.6 ± 0.7 | 0.054 ± 0.003
Carcass | NA | NA | 0.9 ± 1.3
| 3 mg/kg^d^ (72 hours)
Blood | 24.6 ± 3.1 | Unity | 0.044 ± 0.005
Brain | 523.0 ± 23.2 | 21.4 ± 2.4 | 0.15 ± 0.01
Heart | 1,400.0 ± 60.0 | 57.3 ± 7.5 | 0.14 ± 0.01
Kidney | 934.0 ± 78.1 | 38.1 ± 2.9 | 0.25 ± 0.02
Liver | 231.0 ± 4.4 | 9.5 ± 1.1 | 0.4 ± 0.1
Lung | 285.0 ± 35.7 | 11.8 ± 3.1 | 0.037 ± 0.005
Carcass | NA | NA | 11.5 ± 0.9

NA=Not applicable

a Carcass values are based on the residual digested carcass less the equivalents measured in skin, muscle, adipose, and blood.

b Percent dose was calculated using the following values for the mass of total tissue expressed as percent of body weight: adipose, 7.0%; blood, 5.2%; muscle, 48%; and skin, 17%.

c Data are presented as mean ± standard deviation for five rats.

d Data are presented as mean ± standard deviation for three rats.

TABLE J4 Cumulative Excretion of Radioactivity by Male B6C3F_1_ Mice After a Single Intravenous Injection of 0.6 mg/kg [^14^C]-Dicyclohexylcarbodiimide^a^

End of Collection Period (hours) | Urine | Feces | Volatile Organics | Exhaled CO_2_ | Total
8 | 13.5 ± 17.0 | —^b^ | 0.05 ± 0.03 | 0.28 ± 0.08 | 13.9 ± 17.1
24 | 30.4 ± 16.1^c^ | 15.9 ± 2.9 | 0.12 ± 0.03 | 0.32 ± 0.10 | 46.8 ± 14.7
48 | 37.1 ± 13.7^c^ | 21.8 ± 4.7 | 0.18 ± 0.06 | 0.37 ± 0.08 | 59.4 ± 13.4
72 | 49.5 ± 7.8^d^ | 24.6 ± 4.9 | 0.24 ± 0.10 | 0.46 ± 0.08 | 74.9 ± 5.0

a Data are presented as cumulative percentage of the dose (mean ± standard deviation) for five mice.

b No collection was scheduled for this time interval.

c Includes methanol rinse of the urine flask

d Cage rinse is included.

TABLE J5 Tissue Distribution of Radiolabel in Male B6C3F_1_ Mice 72 hours After a Single Intravenous Injection of 0.6 mg/kg [^14^C]-Dicyclohexylcarbodiimide^a^

Tissue | Dicyclohexylcarbodiimide Equivalents in Tissue (ng-Eq/g Tissue) | Tissue:Blood Ratio | Dose in Total Tissue (%)^b^
Adipose | 234.0 ± 166.0 | 25.8 ± 20.2 | 3.72 ± 2.64
Bladder | 40.0 ± 22.8 | 4.25 ± 2.48 | 0.007 ± 0.004
Blood | 10.1 ± 2.36 | Unity | 0.127 ± 0.031
Brain | 60.6 ± 22.4 | 6.53 ± 2.98 | 0.149 ± 0.061
Heart | 189.0 ± 66.7 | 20.2 ± 8.68 | 0.134 ± 0.050
Kidney | 66.4 ± 11.6 | 6.95 ± 2.15 | 0.175 ± 0.027
Liver | 91.8 ± 13.4 | 9.39 ± 2.07 | 0.609 ± 0.058
Lung | 49.6 ± 20.2 | 5.20 ± 2.27 | 0.047 ± 0.020
Muscle | 46.0 ± 19.2 | 4.96 ± 2.35 | 3.45 ± 1.41
Skin | 19.9 ± 2.09 | 2.02 ± 0.28 | 0.483 ± 0.043
Spleen | 26.1 ± 4.49 | 2.75 ± 0.93 | 0.0098 ± 0.0027
Tail | 76.8 ± 42.3 | 7.30 ± 3.12 | 6.29 ± 3.68
Testes | 24.9 ± 6.06 | 2.65 ± 1.00 | 0.032 ± 0.009
Carcass^c^ | NA | NA | 2.12 ± 3.95

NA=Not applicable

a Data are presented as mean ± standard deviation for five mice.

b Percent dose was calculated using the following values for the mass of total tissue expressed as percent of body weight: adipose, 9.6%; blood, 7.6%; muscle, 45.2%; and skin, 14.4%.

c Carcass value is based on the residual digested carcass less the equivalents measured in skin, muscle, adipose, and blood.

TABLE J6 Concentrations of Radiolabel in Blood of Male B6C3F_1_ Mice After a Single Intravenous Injection of 0.4 mg/kg [^14^C]-Dicyclohexylcarbodiimide

Time After Dosing | Dicyclohexylcarbodiimide Equivalents in Blood (ng-Eq/g Blood)
Time After Dosing | Mouse 1 | Mouse 2 | Mouse 3 | Mouse 4 | Mean^a^
1 minute | 6.84 | 740 | 358 | 746 | 463 ± 354
4 minutes | 270 | 205 | 227 | 231 | 233 ± 27
8 minutes | 220 | 187 | 166 | 234 | 202 ± 30.7
20 minutes | 173 | 131 | 145 | 137 | 147 ± 18.5
1 hour | 93.1 | 43.2 | 80.0 | 29.5 | 61.5 ± 30.0
2 hours | 24.5 | 36.6 | 49.2 | 35.0 | 36.3 ± 10.1
8 hours | 56.3 | 18.1 | 12.8 | 25.1 | 28.1 ± 19.5
24 hours | 6.36 | 15.1 | 16.0 | 9.86 | 11.8 ± 4.53
48 hours | 7.69 | 6.95 | 9.55 | 6.93 | 7.78 ± 1.23
| % Dose in Blood
1 minute | 0.266 | 15.7 | 9.71 | 16.8 | 10.6 ± 7.56
4 minutes | 3.62 | 4.80 | 3.70 | 4.17 | 4.07 ± 0.544
8 minutes | 3.53 | 3.62 | 3.44 | 3.84 | 3.61 ± 0.172
20 minutes | 3.25 | 3.44 | 3.52 | 2.70 | 3.23 ± 0.367
1 hour | 1.76 | 1.48 | 1.66 | 1.08 | 1.50 ± 0.301
2 hours | 0.760 | 0.754 | 1.20 | 0.933 | 0.912 ± 0.210
8 hours | 0.734 | 0.255 | 0.343 | 0.501 | 0.459 ± 0.210
24 hours | 0.162 | 0.333 | 0.500 | 0.223 | 0.304 ± 0.148
48 hours | 0.125 | 0.143 | 0.163 | 0.140 | 0.143 ± 0.016

a Data are presented as mean ± standard deviation.

TABLE J7 Cumulative Excretion of Radioactivity by Male F344/N Rats After a Single Dermal Application of [^14^C]-Dicyclohexylcarbodiimide

End of Collection Period (hours) | Urine | Feces | Volatile Organics | Exhaled CO_2_ | Total
| 0.3 mg/kg ^a^
6 | —^b^ | — | 0.6 ± 0.2 | 0.01 ± 0.01 | 0.6 ± 0.2
8 | 0.6 ± 0.2 | — | 0.6 ± 0.2 | 0.01 ± 0.01 | 1.2 ± 0.1
24 | 2.5 ± 0.7 | 0.2 ± 0.1 | 0.9 ± 0.2 | 0.01 ± 0.01 | 3.6 ± 0.7
48 | 4.1 ± 1.1 | 0.5 ± 0.2 | 0.9 ± 0.2 | 0.02 ± 0.01 | 5.6 ± 1.3
72 | 5.8 ± 1.6^c^ | 0.7 ± 0.2 | 1.0 ± 0.2 | 0.02 ± 0.01 | 7.5 ± 1.8
| 3.1 mg/kg ^d^
6 | — | — | 0.8 ± 0.1 | 0.01 ± 0.01 | 0.8 ± 0.1
8 | 0.7 ± 0.3 | — | 0.8 ± 0.1 | 0.01 ± 0.01 | 1.6 ± 0.3
24 | 1.8 ± 0.5 | 0.2 ± 0.1 | 1.1 ± 0.1 | 0.01 ± 0.01 | 3.2 ± 0.6
48 | 2.4 ± 0.7 | 0.4 ± 0.1 | 1.2 ± 0.1 | 0.01 ± 0.01 | 4.0 ± 0.9
72 | 2.9 ± 0.9^c^ | 0.5 ± 0.2 | 1.2 ± 0.1 | 0.02 ± 0.01 | 4.6 ± 1.1

a Data are presented as cumulative percentage of the dose (mean ± standard deviation) for three rats.

b No collection was scheduled for this time interval.

c Cage rinse is included.

d Data are presented as cumulative percentage of the dose (mean ± standard deviation) for five rats.

TABLE J8 Distribution of Radioactivity in Male F344/N Rats 72 Hours After a Single Dermal Application of [^14^C]-Dicyclohexylcarbodiimide

| 0.3 mg/kg^a^ | 3.1 mg/kg^b^
Absorbed Dose
Urine | 5.8 ± 1.6 | 2.9 ± 0.9
Feces | 0.7 ± 0.2 | 0.5 ± 0.2
Exhaled CO_2_ | 0.02 ± 0.01 | 0.02 ± 0.01
Volatile Organics | 1.0 ± 0.2 | 1.2 ± 0.1
Application Site Skin | 16.0 ± 3.5 | 19.1 ± 5.3
Collected Tissues^c^ | 0.3 ± 0.1 | 0.07 ± 0.02
Residual Carcass^d^ | 1.7 ± 1.5 | 0.6 ± 0.4
Total Absorbed Dose | 25.5 ± 6.1 | 24.4 ± 8.3
Total Unabsorbed Dose^e^ | 64.2 ± 6.1 | 65.4 ± 6.8
Total Dose Recovered | 89.7 ± 1.0 | 89.8 ± 3.2

a Data are presented as percentage (mean ± standard deviation) for three rats.

b Data are presented as percentage (mean ± standard deviation) for five rats.

c Kidney, liver, lung, spleen, heart, testes, bladder, brain, and blood

d Dose recovered in the residual carcass less the dose measured in skin, muscle, adipose, and blood

e Total radioactivity in the appliance, skin, skin wash, etc.

TABLE J9 Tissue Distribution of Radiolabel in Male F344/N Rats 72 hours After a Single Dermal Application of [^14^C]-Dicyclohexylcarbodiimide

Tissue | Dicyclohexylcarbodiimide Equivalents in Tissue (ng-Eq/g Tissue) | Tissue:Blood Ratio | Dose in Total Tissue (%)^a^
| 0.3 mg/kg ^b^
Adipose | 2.94 ± 0.64 | 3.18 ± 0.28 | 0.07 ± 0.02
Bladder | 5.44 ± 2.04 | 5.85 ± 1.89 | 0.0008 ± 0.0004
Blood | 0.92 ± 0.16 | Unity | 0.016 ± 0.003
Brain | 3.66 ± 0.67 | 3.98 ± 0.24 | 0.007 ± 0.001
Heart | 14.0 ± 2.7 | 15.2 ± 1.7 | 0.014 ± 0.003
Kidney | 43.9 ± 9.7 | 47.4 ± 3.2 | 0.10 ± 0.02
Liver | 11.7 ± 2.7 | 12.7 ± 1.4 | 0.14 ± 0.04
Lung | 4.42 ± 0.79 | 4.80 ± 0.25 | 0.005 ± 0.001
Muscle | 2.26 ± 0.61 | 2.43 ± 0.24 | 0.36 ± 0.11
Skin | 2.24 ± 0.62 | 2.41 ± 0.39 | 0.13 ± 0.04
Spleen | 3.70 ± 0.74 | 4.01 ± 0.23 | 0.002 ± 0.001
Testes | 2.49 ± 0.30 | 2.72 ± 0.15 | 0.009 ± 0.001
| 3.1 mg/kg ^c^
Adipose | 18.2 ± 7.0 | 5.61 ± 2.05 | 0.04 ± 0.02
Bladder | 10.7 ± 2.8 | 3.47 ± 1.80 | 0.00014 ± 0.00003
Blood | 3.34 ± 0.78 | Unity | 0.006 ± 0.001
Brain | 9.58 ± 2.22 | 2.95 ± 0.69 | 0.002 ± 0.001
Heart | 33.5 ± 4.6 | 10.5 ± 3.2 | 0.003 ± 0.001
Kidney | 81.7 ± 10.9 | 25.5 ± 6.6 | 0.018 ± 0.003
Liver | 35.0 ± 8.6 | 10.7 ± 2.6 | 0.04 ± 0.01
Lung | 13.0 ± 2.1 | 4.08 ± 1.21 | 0.0013 ± 0.0003
Muscle | 5.60 ± 1.03 | 1.75 ± 0.51 | 0.09 ± 0.02
Skin | 22.1 ± 19.6 | 7.31 ± 6.65 | 0.12 ± 0.11
Spleen | 11.0 ± 1.9 | 3.47 ± 1.24 | 0.0006 ± 0.0001
Testes | 6.10 ± 1.81 | 1.88 ± 0.58 | 0.002 ± 0.001

a Percent dose was calculated using the following values for the mass of total tissue expressed as percent of body weight: adipose, 7.0%; blood, 5.2%; muscle, 48%; and skin, 17%.

b Data are presented as mean ± standard deviation for three rats.

c Data are presented as mean ± standard deviation for five rats.

TABLE J10 Cumulative Excretion of Radioactivity by Male B6C3F_1_ Mice After a Single Dermal Application of [^14^C]-Dicyclohexylcarbodiimide

End of Collection Period (hours) | Urine^a^ | Feces | Volatile Organics Trapped by Ethanol | Volatile Organics Trapped by Charcoal | Exhaled CO_2_ | Total
| 0.7 mg/kg ^b^
4 | —^c^ | — | 0.12 ± 0.03 | 0.007 ± 0.007 | 0.10 ± 0.04 | 0.23 ± 0.05
8 | 3.9 ± 3.9 | — | 0.14 ± 0.04 | 0.05 ± 0.04 | 0.12 ± 0.04 | 4.2 ± 4.0
24 | 7.0 ± 6.9 | 10.2 ± 6.8 | 0.20 ± 0.04 | 0.05 ± 0.04 | 0.14 ± 0.03 | 17.6 ± 4.5
48 | 9.0 ± 8.1 | 13.0 ± 7.5 | 0.23 ± 0.04 | 0.05 ± 0.04 | 0.15 ± 0.03 | 22.4 ± 3.9
72 | 11.4 ± 8.7^d^ | 14.0 ± 6.9 | 0.25 ± 0.04 | 0.05 ± 0.04 | 0.17 ± 0.03 | 26.0 ± 3.2
| 6.2 mg/kg ^e^
8 | NS | — | 1.05 ± 0.43 | NA | 0.08 ± 0.03 | 1.14 ± 0.44
24 | 10.5 ± 1.6 | 4.51 ± 0.47 | 1.29 ± 0.49 | NA | 0.13 ± 0.04 | 16.4 ± 2.0
48 | 13.4 ± 1.8 | 6.57 ± 0.89 | 1.40 ± 0.55 | NA | 0.16 ± 0.05 | 21.5 ± 2.2
72 | 22.2 ± 2.4^d^ | 10.2 ± 1.3 | 1.51 ± 0.53 | NA | 0.18 ± 0.05 | 34.0 ± 3.8

NS=No sample was acquired for this time interval. NA=Not applicable.

a Includes methanol rinse of the urine flask.

b Data are presented as cumulative percentage of the dose (mean ± standard deviation) for four mice.

c No collection was scheduled for this time interval.

d Cage rinse is included.

e Data are presented as cumulative percentage of the dose (mean ± standard deviation) for five mice.

TABLE J11 Distribution of Radioactivity in Male B6C3F_1_ Mice 72 Hours After a Single Dermal Application of [^14^C]-Dicyclohexylcarbodiimide^a^

| 0.7 mg/kg | 6.2 mg/kg
Absorbed Dose
Urine | 11.4 ± 8.7 | 22.2 ± 2.4
Feces | 14.0 ± 6.9 | 10.2 ± 1.3
Exhaled CO_2_ | 0.17 ± 0.03 | 0.2 ± 0.1
Volatile Organics Trapped by Ethanol | 0.25 ± 0.04 | 1.5 ± 0.5
Volatile Organics Trapped by Charcoal | 0.05 ± 0.04 | —^b^
Application Site Skin | 2.0 ± 0.4 | 3.2 ± 1.5
Collected Tissues^c^ | 1.5 ± 0.12 | 4.5 ± 2.8
Residual Carcass^d^ | 0.5 ± 0.5 | 0.0 ± 0.0
Total Absorbed Dose | 29.9 ± 3.3 | 41.2 ± 4.8
Total Unabsorbed Dose^e^ | 58.7 ± 4.2 | 42.9 ± 4.8
Total Dose Recovered | 88.6 ± 5.7 | 84.1 ± 3.2

a Data are presented as percentage (mean ± standard deviation) for five mice.

b No sample was collected.

c Skin, muscle, adipose, and blood

d Dose recovered in the residual carcass less the dose measured in skin, muscle, adipose, and blood

e Total radioactivity in the appliance, skin, skin wash, etc.

TABLE J12 Tissue Distribution of Radiolabel in Male B6C3F_1_ Mice 72 Hours After a Single Dermal Application of [^14^C]-Dicyclohexylcarbodiimide

Tissue^a^ | Dicyclohexylcarbodiimide Equivalents in Tissue (ng-Eq/g Tissue) | Tissue:Blood Ratio | Dose in Total Tissue (%)^b^
| 0.7 mg/kg ^c^
Adipose | 26.7 ± 15.1 | 7.69 ± 5.84 | 0.33 ± 0.24
Bladder | 21.2 ± 8.7 | 5.37 ± 2.59 | 0.004 ± 0.003
Blood | 4.29 ± 1.57 | Unity | 0.04 ± 0.01
Brain | 5.29 ± 0.42 | 1.33 ± 0.37 | 0.013 ± 0.001
Heart | 28.3 ± 9.5 | 6.68 ± 0.93 | 0.022 ± 0.007
Kidney | 34.2 ± 16.5 | 7.83 ± 1.03 | 0.07 ± 0.03
Liver | 103.0 ± 78.1 | 22.1 ± 7.9 | 0.6 ± 0.3
Lung | 6.98 ± 1.85 | 1.68 ± 0.30 | 0.006 ± 0.002
Muscle | 5.14 ± 1.24 | 1.24 ± 0.16 | 0.30 ± 0.04
Skin | 9.52 ± 1.69 | 2.37 ± 0.63 | 0.18 ± 0.04
Spleen | 9.67 ± 5.66 | 2.17 ± 0.52 | 0.003 ± 0.002
Testes | 5.91 ± 0.81 | 1.46 ± 0.31 | 0.0068 ± 0.0008
Carcass | NA | NA | 0.5 ± 0.5
Application Site Skin | 27.9 ± 5.2 | 6.85 ± 1.50 | 1.96 ± 0.43
| 6.2 mg/kg ^d^
Adipose | 542 ± 105 | 19.9 ± 3.7 | 0.8 ± 0.1
Bladder | 210.0 ± 69.8 | 7.7 ± 2.6 | 0.0027 ± 0.0007
Blood | 27.3 ± 1.1 | Unity | 0.033 ± 0.002
Brain | 81.0 ± 9.3 | 3.0 ± 0.4 | 0.021 ± 0.002
Heart | 352 ± 109 | 12.9 ± 3.7 | 0.020 ± 0.002
Kidney | 253.0 ± 29.3 | 9.3 ± 0.9 | 0.057 ± 0.005
Liver | 488.0 ± 36.2 | 17.9 ± 1.3 | 0.43 ± 0.07
Lung | 84.3 ± 11.6 | 3.1 ± 0.4 | 0.008 ± 0.002
Muscle | 80.0 ± 8.1 | 2.9 ± 0.3 | 0.59 ± 0.07
Skin | 1,050 ± 1,130 | 37.9 ± 39.5 | 2.5 ± 2.8
Spleen | 85.0 ± 14.5 | 3.1 ± 0.6 | 0.0025 ± 0.0003
Testes | 83.7 ± 10.2 | 3.1 ± 0.3 | 0.009 ± 0.001
Carcass | NA | NA | 0.0 ± 0.0
Application Site Skin | 403 ±183 | 14.9 ± 6.9 | 3.2 ± 1.5

NA=Not applicable

a Carcass values are based on the residual digested carcass less the equivalents measured in skin, muscle, adipose, and blood.

b Percent dose was calculated using the following values for the mass of total tissue expressed as percent of body weight: adipose, 9.6%; blood, 7.6%; muscle, 45.2%; and skin, 14.4%.

c Data are presented as mean ± standard deviation for four mice.

d Data are presented as mean ± standard deviation for five mice.