# APPENDIX I CHEMICAL CHARACTERIZATION AND DOSE FORMULATION STUDIES

## Procurement and Characterization

### Dicyclohexylcarbodiimide

Dicyclohexylcarbodiimide, lot 00929TZ, was obtained from Aldrich Chemical Company (Milwaukee, WI) and was used in the 3-, 13-, and 20-week studies; lot 60104-1 was obtained from Chem-Impex International (Wood Dale, IL) and was used in the 27-week study. Identity and purity analyses were conducted by the analytical chemistry laboratory, Midwest Research Institute (Kansas City, MO), and by the study laboratories, Microbiological Associates, Inc. (Bethesda, MD; 3-, 13-, and 20-week studies) and BioReliance Corporation (Rockville, MD; 27-week study). Reports on analyses performed in support of the dicyclohexylcarbodiimide studies are on file at the National Institute of Environmental Health Sciences.

The chemical, a colorless crystalline material, was identified as dicyclohexylcarbodiimide by the study laboratories using infrared (IR) spectroscopy (lots 00929TZ and 60104-1) and by the analytical chemistry laboratory using IR and proton nuclear magnetic resonance (NMR) spectroscopy (lot 60104-1). All spectra were consistent with the literature spectra (Aldrich, 1981a, 1985, 1993). Representative IR and NMR spectra are presented in Figures I1 and I2.

The purity of lot 00929TZ was determined by the study laboratory using gas chromatography (GC) by system A (Table I1). The purity of lot 60104-1 was determined by the analytical chemistry laboratory using high-performance liquid chromatography (HPLC) by system 1, and purity relative to a frozen reference standard of the same lot was measured by the study laboratory using HPLC by system 2 (Table I2).

For lot 00929TZ, GC by system A indicated one major peak, three major impurities (ranging from 0.08% to 0.27% of the total peak area), and two minor impurities. The overall purity of lot 00929TZ was determined to be 99.5%. For lot 60104-1, HPLC by system 1 indicated a major peak and six impurity peaks with a combined area of 1.69% relative to the total peak area. The overall purity of lot 60104-1 was estimated to be greater than 98%.

To ensure stability, the bulk chemical was stored at room temperature, under a nitrogen head space, protected from light as recommended by the manufacturers. Periodic analyses of the bulk chemical were performed by the study laboratories using GC by system A for the 3-, 13-, and 20 week studies (lot 00929TZ) and HPLC by system 2 for the 27-week studies (lot 60104-1). No degradation of the bulk chemical was detected.

### Anhydrous Ethanol

Anhydrous ethanol was obtained from Pharmco Products, Inc. (Brookfield, CT). Identity and purity analyses of all lots used in the 27-week study were conducted by the study laboratory. The chemical, a clear liquid, was identified as ethanol by IR spectroscopy; the sample spectra were consistent with a literature spectrum (Aldrich, 1981b). The purity of each lot was analyzed using GC by system B. The overall purity of each analyzed lot was determined to be greater than 99.9%.

## Preparation and Analysis of Dose Formulations

Dose formulations were prepared twice (3-week studies), approximately every 2 weeks (13-week studies), every 3 weeks (20-week study), and monthly (27-week study) by mixing dicyclohexylcarbodiimide with anhydrous ethanol to give the required concentration (Table I3). The dose formulations were stored in sealed vials under a headspace of inert gas for up to 28 days (3- and 13-week studies) or 35 days (20- and 27-week studies) at room temperature for the 3-, 13-, and 20-week studies, and until April 1, 1999 (week 13), for the 27-week study; subsequent storage for the 27-week study was at −20° C.

Because the dose formulations were true solutions of the test article in ethanol, homogeneity studies were not performed. Stability studies of 0.38, 2, and 7 mg/mL formulations of lot 00929TZ were conducted by the study laboratory using GC by system C. Stability was confirmed for up to 35 days for dose formulations stored at room temperature in sealed containers under a nitrogen headspace and for up to 3 hours when exposed to light and air at room temperature.

Periodic analyses of the dose formulations of dicyclohexylcarbodiimide were conducted by the study laboratories using GC by system C. During the 3-week studies, the dose formulations were analyzed once; all five dose formulations were within 10% of the target concentrations (Table I4). Animal room samples of these dose formulations were also analyzed; all 10 animal room samples for rats and mice were within 10% of the target concentrations. During the 13-week studies, the dose formulations were analyzed at the beginning, midpoint, and end of the studies; animal room samples of these dose formulations were also analyzed (Table I5). Of the dose formulations analyzed, all 15 for rats and all 15 for mice were within 10% of the target concentrations; all 13 animal room samples for rats and 12 of 13 for mice were within 10% of the target concentrations. One aberrant mouse animal room sample was determined to be due to evaporation from an inadequately sealed vial. Dose formulations were analyzed at the beginning, midpoint, and end of the 20-week study; animal room samples of these dose formulations were also analyzed (Table I6). All 15 dose formulations and all 13 animal room samples were within 10% of the target concentrations. Dose formulations in the initial set and every other set thereafter were analyzed in the 27-week study; animal room samples of these dose formulations were also analyzed (Table I7). All 14 dose formulations analyzed were within 10% of the target concentrations; 8 of 14 animal room samples were not within 10% of target concentrations. Unusual degradation was observed in the animal room samples from the formulations prepared on February 24, 1999, and March 24, 1999. Attempts to discover the cause of the degradation in the formulations were not conclusive, but the most likely cause, water in the anhydrous ethanol, was eliminated. Starting on April 2, 1999, all dose formulations were stored at −20° C as an additional precaution against degradation.

FIGURE I1 Infrared Absorption Spectrum of Dicyclohexylcarbodiimide

FIGURE I2 ^1^H Nuclear Magnetic Resonance Spectrum of Dicyclohexylcarbodiimide

TABLE I1 Gas Chromatography Systems Used in the Dermal Studies of Dicyclohexylcarbodiimide^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization | HP-1, 5 m × 0.53 mm (Hewlett-Packard Company, Palo Alto, CA) | Nitrogen at 17.5 mL/minute | 135° C to 235° C at 10° C/minute, held for 10 minutes
System B
Flame ionization | Alltech Econo-Cap Carbowax, 30 m × 0.53 mm, 1.2-μm film (Alltech, Deerfield, IL) | Nitrogen at 6 mL/minute | Isothermal at 62° C
System C
Flame ionization | HP-1, 5 m × 0.53 mm, 2.65-μm film (Hewlett-Packard Company) | Nitrogen at 17.5 mL/minute | Isothermal at 140° C

a All gas chromatographs were manufactured by Hewlett-Packard Company (Palo Alto, CA)

TABLE I2 High-Performance Liquid Chromatography Systems Used in the Dermal Studies of Dicyclohexylcarbodiimide^a^

Detection System | Column | Solvent System
System 1
Ultraviolet (233 nm) light | Alltech Alltima C18, 250 mm × 3.2 mm, 5 μm, heated to 40° C (Alltech, Deerfield, IL) | Acetonitrile:water (50:50), isocratic flow rate 1.0 mL/minute
System 2
Ultraviolet (233 nm) light | Alltech Alltima C18, 250 mm × 3.2 mm, 5 μm, heated to 40° C (Alltech) | Acetonitrile:water (80:20), isocratic flow rate 1.0 mL/minute

a The high-performance liquid chromatographs were manufactured by Waters Corp. (Milford, MA) (system 1) or Hewlett-Packard Company (Palo Alto, CA) (system 2).

TABLE I3 Preparation and Storage of Dose Formulations in the Dermal Studies of Dicyclohexylcarbodiimide

3-Week Studies | 13-Week Studies | 20-Week Study | 27-Week Study
Preparation
A weighed amount of dicyclohexylcarbodiimide was dissolved in absolute ethanol to prepare the highest dose concentration formulation; lower dose formulations were prepared by diluting aliquots of this preparation with absolute ethanol. Dose formulations were prepared twice. | Same as 3-week studies except that all dose formulations were prepared at least every 2 weeks. | Same as 3-week studies except that all dose formulations were prepared every 3 weeks. | A weighed amount of dicyclohexylcarbodiimide was dissolved in absolute ethanol to obtain the appropriate concentration for each dose formulation. Dose formulations were prepared monthly.
Chemical Lot Number
00929TZ | 00929TZ | 00929TZ | 60104-1
Maximum Storage Time
28 days | 28 days | 35 days | 35 days
Storage Conditions
Stored at room temperature, under nitrogen headspace, protected from light | Stored at room temperature, under nitrogen headspace, protected from light | Stored at room temperature, under nitrogen headspace, protected from light | Stored at room temperature from December 30, 1998, to April 1, 1999, then stored at -20° C, under nitrogen headspace, protected from light
Study Laboratory
Microbiological Associates, Inc. (Bethesda, MD) | Microbiological Associates, Inc. (Bethesda, MD) | Microbiological Associates, Inc. (Bethesda, MD) | BioReliance Corporation (Rockville, MD)

TABLE I4 Results of Analyses of Dose Formulations Administered to F344/N Rats and B6C3F_1_ Mice in the 3-Week Dermal Studies of Dicyclohexylcarbodiimide

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
June 23, 1994 | June 23, 1994 | 2 | 1.95 | −3
June 23, 1994 | June 23, 1994 | 6 | 6.02 | 0
June 23, 1994 | June 23, 1994 | 17 | 16.3 | −4
June 23, 1994 | June 23, 1994 | 50 | 49.2 | −2
June 23, 1994 | June 23, 1994 | 150 | 147 | −2
June 23, 1994 | July 6, 1994^b^ | 2 | 1.91 | −5
June 23, 1994 | July 6, 1994^b^ | 6 | 6.05 | +1
June 23, 1994 | July 6, 1994^b^ | 17 | 16.0 | −6
June 23, 1994 | July 6, 1994^b^ | 50 | 47.7 | −5
June 23, 1994 | July 6, 1994^b^ | 150 | 135 | −10
June 23, 1994 | July 6, 1994^c^ | 2 | 1.92 | −4
June 23, 1994 | July 6, 1994^c^ | 6 | 6.10 | +2
June 23, 1994 | July 6, 1994^c^ | 17 | 16.3 | −4
June 23, 1994 | July 7, 1994^c^ | 50 | 46.6 | −7
June 23, 1994 | July 7, 1994^c^ | 150 | 141 | −6

a Results of duplicate analyses. For rats, dosing volume=0.3 mL; 2 mg/mL=0.6 mg, 6 mg/mL=1.8 mg, 17 mg/mL=5.1 mg, 50 mg/mL=15 mg, 150 mg/mL=45 mg. For mice, dosing volume = 0.1 mL; 2 mg/mL=0.2 mg, 6 mg/mL=0.6 mg, 17 mg/mL=1.7 mg, 50 mg/mL=5 mg, 150 mg/mL=15 mg.

b Animal room samples for rats

c Animal room samples for mice

TABLE I5 Results of Analyses of Dose Formulations Administered to F344/N Rats and B6C3F_1_ Mice in the 13-Week Dermal Studies of Dicyclohexylcarbodiimide

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
Rats
September 14, 1994 | September 14, 1994 | 1.5 | 1.47 | −2
September 14, 1994 | September 14, 1994 | 3 | 2.91 | −3
September 14, 1994 | September 14, 1994 | 6 | 5.91 | −2
September 14, 1994 | September 14, 1994 | 12 | 11.6 | −3
September 14, 1994 | September 14, 1994 | 24 | 23.7 | −1
September 14, 1994 | October 3, 1994^b^ | 1.5 | 1.45 | −3
September 14, 1994 | October 3, 1994^b^ | 3 | 2.89 | −4
September 14, 1994 | October 3, 1994^b^ | 6 | 5.97 | −1
September 14, 1994 | October 3, 1994^b^ | 12 | 11.8 | −2
September 14, 1994 | October 3, 1994^b^ | 24 | 23.6 | −2
October 19, 1994 | October 19, 1994 | 1.5 | 1.47 | −2
October 19, 1994 | October 19, 1994 | 3 | 2.91 | −3
October 19, 1994 | October 19, 1994 | 6 | 5.64 | −6
October 19, 1994 | October 19, 1994 | 12 | 11.6 | −3
October 19, 1994 | October 19, 1994 | 24 | 23.8 | −1
October 19, 1994 | November 9-10, 1994^b^ | 1.5 | 1.49 | −1
October 19, 1994 | November 9-10, 1994^b^ | 3 | 3.02 | +1
October 19, 1994 | November 9-10, 1994^b^ | 6 | 5.90 | −2
October 19, 1994 | November 9-10, 1994^b^ | 12 | 12.1 | +1
November 30, 1994 | November 30, 1994 | 1.5 | 1.47 | −2
November 30, 1994 | November 30, 1994 | 3 | 3.02 | +1
November 30, 1994 | November 30, 1994 | 6 | 6.00 | 0
November 30, 1994 | November 30, 1994 | 12 | 12.0 | 0
November 30, 1994 | November 30, 1994 | 24 | 22.8 | −5
November 30, 1994 | December 29, 1994^b^ | 1.5 | 1.46 | −3
November 30, 1994 | December 29, 1994^b^ | 3 | 2.88 | −4
November 30, 1994 | December 29, 1994^b^ | 6 | 5.94 | −1
November 30, 1994 | December 29, 1994^b^ | 12 | 11.6 | −3
Mice
September 14, 1994 | September 14, 1994 | 1.5 | 1.47 | −2
September 14, 1994 | September 14, 1994 | 3 | 2.91 | −3
September 14, 1994 | September 14, 1994 | 6 | 5.91 | −2
September 14, 1994 | September 14, 1994 | 12 | 11.6 | −3
September 14, 1994 | October 3, 1994^b^ | 1.5 | 1.46 | −3
September 14, 1994 | October 3, 1994^b^ | 3 | 2.97 | −1
September 14, 1994 | October 3, 1994^b^ | 6 | 5.91 | −2
September 14, 1994 | October 3, 1994^b^ | 12 | 11.8 | −2
September 19, 1994 | September 19, 1994 | 0.75 | 0.743 | −1
September 19, 1994 | October 3, 1994^b^ | 0.75 | 0.761 | +1
October 19, 1994 | October 19, 1994 | 0.75 | 0.747 | 0
October 19, 1994 | October 19, 1994 | 1.5 | 1.47 | −2
October 19, 1994 | October 19, 1994 | 3 | 2.91 | −3
October 19, 1994 | October 19, 1994 | 6 | 5.64 | −6
October 19, 1994 | October 19, 1994 | 12 | 11.6 | −3
October 19, 1994 | November 9, 1994^b^ | 0.75 | 0.762 | +2
October 19, 1994 | November 9, 1994^b^ | 1.5 | 1.53 | +2
October 19, 1994 | November 9, 1994^b^ | 3 | 3.04 | +1
October 19, 1994 | November 9, 1994^b^ | 6 | 5.98 | 0
November 30, 1994 | November 30, 1994 | 1.5 | 1.47 | −2
November 30, 1994 | November 30, 1994 | 3 | 3.02 | +1
November 30, 1994 | November 30, 1994 | 6 | 6.00 | 0
November 30, 1994 | November 30, 1994 | 12 | 12.0 | 0
November 30, 1994 | December 29, 1994^b^ | 1.5 | 1.47 | −2
November 30, 1994 | December 29, 1994^b^ | 3 | 3.79^c^ | +26
November 30, 1994 | December 29, 1994^b^ | 6 | 6.09 | +2
December 1, 1994 | December 1, 1994 | 0.75 | 0.771 | +3
December 1, 1994 | December 29, 1994^b^ | 0.75 | 0.757 | +1

a Results of duplicate analyses. For rats, dosing volume=0.5 mL/kg; 1.5 mg/mL=0.75 mg/kg, 3.0 mg/mL=1.5 mg/kg, 6.0 mg/mL=3 mg/kg, 12 mg/m =6 mg/kg, 24 mg/mL=12 mg/kg. For mice, dosing volume=2.0 mL/kg; 0.75 mg/mL=1.5 mg/kg, 1.5 mg/mL=3 mg/kg, 3.0 mg/mL=6 mg/kg, 6.0 mg/mL=12 mg/kg, 12 mg/mL=24 mg/kg

b Animal room samples

c High value due to evaporation of vehicle from inadequately sealed vial

TABLE I6 Results of Analyses of Dose Formulations Administered to Female Tg.AC Hemizygous Mice in the 20-Week Dermal Study of Dicyclohexylcarbodiimide

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
June 6, 1995 | June 7, 1995 | 0.38 | 0.384 | +1
June 6, 1995 | June 7, 1995 | 0.75 | 0.770 | +3
June 6, 1995 | June 7, 1995 | 1.5 | 1.50 | 0
June 6, 1995 | June 7, 1995 | 3 | 3.06 | +2
June 6, 1995 | June 7, 1995 | 6 | 5.99 | 0
June 6, 1995 | July 10, 1995^b^ | 0.38 | 0.364 | −4
June 6, 1995 | July 10, 1995^b^ | 0.75 | 0.705 | −6
June 6, 1995 | July 10, 1995^b^ | 1.5 | 1.51 | +1
June 6, 1995 | July 10, 1995^b^ | 3 | 3.07 | +2
June 6, 1995 | July 10, 1995^b^ | 6 | 5.89 | −2
July 18, 1995 | July 19, 1995 | 0.38 | 0.380 | 0
July 18, 1995 | July 19, 1995 | 0.75 | 0.708 | −6
July 18, 1995 | July 19, 1995 | 1.5 | 1.54 | +3
July 18, 1995 | July 19, 1995 | 3 | 3.03 | +1
July 18, 1995 | July 19, 1995 | 6 | 5.98 | 0
July 18, 1995 | August 18, 1995^b^ | 0.38 | 0.368 | −3
July 18, 1995 | August 18, 1995^b^ | 0.75 | 0.741 | −1
July 18, 1995 | August 18, 1995^b^ | 1.5 | 1.52 | +1
July 18, 1995 | August 18, 1995^b^ | 3 | 3.00 | 0
July 18, 1995 | August 18, 1995^b^ | 6 | —^c^ | —
August 29, 1995 | August 29, 1995 | 0.38 | 0.386 | +2
August 29, 1995 | August 29, 1995 | 0.75 | 0.754 | +1
August 29, 1995 | August 29, 1995 | 1.5 | 1.52 | +1
August 29, 1995 | August 29, 1995 | 3 | 2.90 | −3
August 29, 1995 | August 29, 1995 | 6 | 6.04 | +1
August 29, 1995 | September 29, 1995^b^ | 0.38 | 0.361 | −5
August 29, 1995 | September 29, 1995^b^ | 0.75 | 0.729 | −3
August 29, 1995 | September 29, 1995^b^ | 1.5 | 1.46 | −3
August 29, 1995 | September 29, 1995^b^ | 3 | 2.84 | −5
August 29, 1995 | September 29, 1995^b^ | 6 | — | —

a Results of duplicate analyses. Dosing volume=2.0 mL/kg; 0.38 mg/mL=0.75 mg/kg, 0.75 mg/mL=1.5 mg/kg, 1.5 mg/mL=3 mg/kg, 3.0 mg/mL=6 mg/kg, 6.0 mg/mL=12 mg/kg

b Animal room samples

c Due to the severity of skin lesions, application of the test article was discontinued after 8 days.

TABLE I7 Results of Analyses of Dose Formulations Administered to Female p53 Haploinsufficient Mice in the 27-Week Dermal Study of Dicyclohexylcarbodiimide

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
December 30, 1998 | December 30, 1998 | 0.38 | 0.383 | +1
December 30, 1998 | December 30, 1998 | 0.75 | 0.806 | +7
December 30, 1998 | December 30, 1998 | 1.5 | 1.55 | +3
December 30, 1998 | December 30, 1998 | 3 | 3.06 | +2
December 30, 1998 | December 30, 1998 | 6 | 6.16 | +3
December 30, 1998 | February 4, 1999^b^ | 0.38 | 0.397 | +4
December 30, 1998 | February 4, 1999^b^ | 0.75 | 0.888 | +18
December 30, 1998 | February 4, 1999^b^ | 1.5 | 1.61 | +7
December 30, 1998 | February 4, 1999^b^ | 3 | 3.08 | +3
December 30, 1998 | February 4, 1999^b^ | 6 | 6.39 | +7
February 24, 1999 | February 24, 1999 | 0.38 | 0.386 | +2
February 24, 1999 | February 24, 1999 | 0.75 | 0.760 | +1
February 24, 1999 | February 24, 1999 | 1.5 | 1.54 | +3
February 24, 1999 | April 1, 1999^b^ | 0.38 | 0.182 | −52
February 24, 1999 | April 1, 1999^b^ | 0.75 | 0.423 | −44
February 24, 1999 | April 1, 1999^b^ | 1.50 | 0.780 | −48
March 24, 1999 | April 8, 1999^b^ | 0.38 | 0.259 | −32
March 24, 1999 | April 8, 1999^b^ | 0.75 | 0.513 | −32
March 24, 1999 | April 8, 1999^b^ | 1.5 | 1.15 | −23
April 12, 1999 | April 12, 1999 | 0.38 | 0.415 | +9
April 12, 1999 | April 12, 1999 | 0.75 | 0.717 | −4
April 12, 1999 | April 12, 1999 | 1.5 | 1.53 | +2
June 14, 1999 | June 14, 1999 | 0.38 | 0.414 | +9
June 14, 1999 | June 14, 1999 | 0.75 | 0.684 | −9
June 14, 1999 | June 14, 1999 | 1.5 | 1.41 | −6
June 14, 1999 | July 15, 1999^b^ | 0.38 | 0.407 | +7
June 14, 1999 | July 15, 1999^b^ | 0.75 | 0.653 | −13
June 14, 1999 | July 15, 1999^b^ | 1.5 | 1.45 | −3

a Results of duplicate analyses. Dosing volume=2.0 mL/kg; 0.38 mg/mL=0.75 mg/kg, 0.75 mg/mL=1.5 mg/kg, 1.5 mg/mL=3 mg/kg, 3.0 mg/mL=6 mg/kg, 6.0 mg/mL=12 mg/kg

b Animal room samples