# APPENDIX H REPRODUCTIVE TISSUE EVALUATIONS AND ESTROUS CYCLE CHARACTERIZATION

TABLE H1 Summary of Reproductive Tissue Evaluations for Male F344/N Rats in the 13-Week Dermal Study of Dicyclohexylcarbodiimide^a^

| Vehicle Control | 1.5 mg/kg | 3 mg/kg | 6 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 330 ± 5 | 334 ± 6 | 325 ± 7 | 300 ± 4^**^
L. Cauda epididymis | 0.1421 ± 0.0035 | 0.1437 ± 0.0042 | 0.1493 ± 0.0045 | 0.1474 ± 0.0039
L. Epididymis | 0.4774 ± 0.0110 | 0.4690 ± 0.0100 | 0.4723 ± 0.0037 | 0.4641 ± 0.0081
L. Testis | 1.4409 ± 0.0204 | 1.4478 ± 0.0208 | 1.5049 ± 0.0267 | 1.4022 ± 0.0194
Spermatid measurements
Spermatid heads (10^7^/g testis) | 9.76 ± 0.30 | 9.43 ± 0.22 | 9.14 ± 0.21 | 10.11 ± 0.38
Spermatid heads (10^7^/testis) | 14.06 ± 0.48 | 13.63 ± 0.28 | 13.73 ± 0.28 | 14.16 ± 0.52
Spermatid count (mean/10^-4^ mL suspension) | 70.30 ± 2.42 | 68.15 ± 1.40 | 68.65 ± 1.37 | 70.78 ± 2.59
Epididymal spermatozoal measurements
Motility (%) | 86.93 ± 0.36 | 86.79 ± 0.61 | 86.69 ± 0.47 | 87.28 ± 1.12
Concentration (10^6^/g cauda epididymal tissue) | 513 ± 14 | 515 ± 67 | 404 ± 48 | 404 ± 34

** Significantly different (P≤0.01) from the vehicle control group by Williams’ test

a Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

TABLE H2 Estrous Cycle Characterization for Female F344/N Rats in the 13-Week Dermal Study of Dicyclohexylcarbodiimide^a^

| Vehicle Control | 1.5 mg/kg | 3 mg/kg | 6 mg/kg
n | 10 | 10 | 10 | 10
Necropsy body wt (g) | 186 ± 3 | 190 ± 4 | 193 ± 3 | 192 ± 4
Estrous cycle length (days) | 4.95 ± 0.05 | 5.00 ± 0.00 | 5.00 ± 0.00 | 5.00 ± 0.00
Estrous stages (% of cycle)
Diestrus | 40.8 | 44.2 | 45.0 | 45.0
Proestrus | 19.2 | 17.5 | 18.3 | 18.3
Estrus | 21.7 | 20.8 | 20.8 | 18.3
Metestrus | 18.3 | 17.5 | 15.8 | 18.3

a Necropsy body weight and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weight) or Dunn’s test (estrous cycle length). By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages.

TABLE H3 Summary of Reproductive Tissue Evaluations for Male B6C3F_1_ Mice in the 13-Week Dermal Study of Dicyclohexylcarbodiimide^a^

| Vehicle Control | 3 mg/kg | 6 mg/kg | 12 mg/kg
n | 9 | 8 | 10 | 10
Weights (g)
Necropsy body wt | 33.8 ± 0.6 | 32.9 ± 0.6 | 31.5 ± 0.5^**^ | 30.4 ± 0.5^**^
L. Cauda epididymis | 0.0189 ± 0.0011 | 0.0182 ± 0.0013 | 0.0174 ± 0.0008 | 0.0163 ± 0.0007
L. Epididymis | 0.0539 ± 0.0012 | 0.0515 ± 0.0016 | 0.0492 ± 0.0013^*^ | 0.0467 ± 0.0018^**^
L. Testis | 0.1128 ± 0.0034 | 0.1138 ± 0.0025 | 0.1150 ± 0.0023 | 0.1095 ± 0.0026
Spermatid measurements
Spermatid heads (10^7^/g testis) | 16.16 ± 0.33 | 16.09 ± 0.52 | 15.90 ± 0.47 | 15.82 ± 0.41
Spermatid heads (10^7^/testis) | 1.82 ± 0.05 | 1.83 ± 0.06 | 1.82 ± 0.05 | 1.73 ± 0.04
Spermatid count (mean/10^-4^ mL suspension) | 56.83 ± 1.64 | 57.13 ± 1.81 | 56.98 ± 1.55 | 53.93 ± 1.16
Epididymal spermatozoal measurements
Motility (%) | 88.98 ± 0.24 | 88.35 ± 0.19 | 87.32 ± 0.38^**^ | 88.34 ± 0.33
Concentration (10^6^/g cauda epididymal tissue) | 918 ± 77 | 921 ± 85 | 937 ± 56 | 1,052 ± 65

* Significantly different (P≤0.05) from the vehicle control group by Williams’ test

** Significantly different (P≤0.01) from the vehicle control group by Williams’ test (body and left epididymal weights) or Dunn’s test (epididymal spermatozoal motility)

a Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (left cauda epididymal and testis weights) or Dunn’s test (spermatid measurements and epididymal spermatozoal concentration).

TABLE H4 Estrous Cycle Characterization for Female B6C3F_1_ Mice in the 13-Week Dermal Study of Dicyclohexylcarbodiimide^a^

| Vehicle Control | 3 mg/kg | 6 mg/kg | 12 mg/kg
n | 10 | 10 | 10 | 10
Necropsy body wt (g) | 28.8 ± 0.9 | 27.8 ± 0.5 | 27.7 ± 0.3 | 26.5 ± 0.4^*^
Estrous cycle length (days) | 4.00 ± 0.00 | 4.50 ± 0.50 | 4.05 ± 0.05 | 4.25 ± 0.21
Estrous stages (% of cycle)
Diestrus | 30.0 | 29.2 | 28.3 | 26.7
Proestrus | 21.7 | 20.8 | 15.8 | 20.0
Estrus | 24.2 | 25.0 | 31.7 | 28.3
Metestrus | 24.2 | 25.0 | 23.3 | 25.0
Uncertain diagnoses | 0.0 | 0.0 | 0.8 | 0.0

* Significantly different (P≤0.05) from the vehicle control group by Dunnett’s test

a Necropsy body weight and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group for estrous cycle length are not significant by Dunn’s test. By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages.