# APPENDIX G ORGAN WEIGHTS AND ORGAN-WEIGHT-TO-BODY-WEIGHT RATIOS

TABLE G1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for F344/N Rats in the 3-Week Dermal Study of Dicyclohexylcarbodiimide^a^

| Vehicle Control | 0.6 mg/animal | 1.8 mg/animal | 5.1 mg/animal
n | 5 | 5 | 5 | 1
Male
Necropsy body wt | 258 ± 9 | 261 ± 8 | 254 ± 9 | 191
Adrenal gland
Absolute | 0.052 ± 0.002 | 0.047 ± 0.002 | 0.052 ± 0.004 | 0.071
Relative | 0.203 ± 0.009 | 0.183 ± 0.011 | 0.206 ± 0.016 | 0.372
Heart
Absolute | 0.818 ± 0.018 | 0.827 ± 0.025 | 0.858 ± 0.036 | 0.803
Relative | 3.176 ± 0.067 | 3.170 ± 0.052 | 3.373 ± 0.059 | 4.204
R. Kidney
Absolute | 1.132 ± 0.035 | 1.189 ± 0.034 | 1.210 ± 0.045 | 1.013
Relative | 4.389 ± 0.047 | 4.559 ± 0.034 | 4.765 ± 0.109^**^ | 5.304
Liver
Absolute | 13.625 ± 0.542 | 13.584 ± 0.527 | 14.335 ± 0.461
Relative | 52.792 ± 0.905 | 52.032 ± 0.938 | 56.560 ± 1.818
Lung
Absolute | 1.239 ± 0.047 | 1.361 ± 0.039 | 1.298 ± 0.061
Relative | 4.801 ± 0.086 | 5.229 ± 0.171 | 5.112 ± 0.195
R. Testis
Absolute | 1.374 ± 0.021 | 1.330 ± 0.032 | 1.349 ± 0.038
Relative | 5.339 ± 0.108 | 5.101 ± 0.060 | 5.316 ± 0.060
Thymus
Absolute | 0.463 ± 0.032 | 0.482 ± 0.042 | 0.404 ± 0.024
Relative | 1.787 ± 0.067 | 1.845 ± 0.141 | 1.596 ± 0.103
Female
Necropsy body wt | 165 ± 3 | 164 ± 8 | 155 ± 5
Adrenal gland
Absolute | 0.054 ± 0.001 | 0.055 ± 0.002 | 0.056 ± 0.006
Relative | 0.327 ± 0.012 | 0.335 ± 0.018 | 0.365 ± 0.045
Heart
Absolute | 0.614 ± 0.018 | 0.608 ± 0.032 | 0.613 ± 0.019
Relative | 3.721 ± 0.097 | 3.700 ± 0.072 | 3.967 ± 0.087
R. Kidney
Absolute | 0.748 ± 0.020 | 0.763 ± 0.025 | 0.751 ± 0.014
Relative | 4.533 ± 0.080 | 4.668 ± 0.131 | 4.876 ± 0.174
Liver
Absolute | 7.962 ± 0.131 | 7.346 ± 0.198 | 7.495 ± 0.199
Relative | 48.313 ± 1.002 | 44.962 ± 1.225 | 48.528 ± 0.999
Lung
Absolute | 1.027 ± 0.021 | 1.084 ± 0.076 | 0.989 ± 0.020
Relative | 6.232 ± 0.174 | 6.659 ± 0.539 | 6.427 ± 0.269
Thymus
Absolute | 0.378 ± 0.017 | 0.373 ± 0.032 | 0.334 ± 0.015
Relative | 2.290 ± 0.090 | 2.258 ± 0.107 | 2.171 ± 0.124

** Significantly different (P≤0.01) from the vehicle control group by Williams’ test

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error); no data available for the 5.1 (female), 15, and 45 mg/animal groups due to 100% mortality.

TABLE G2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for F344/N Rats in the 13-Week Dermal Study of Dicyclohexylcarbodiimide^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3mg/kg | 6 mg/kg
n | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 330 ± 5 | 337 ± 6 | 334 ± 6 | 325 ± 7 | 300 ± 4^**^
Heart
Absolute | 1.008 ± 0.021 | 1.068 ± 0.013 | 0.995 ± 0.019 | 1.076 ± 0.034 | 0.998 ± 0.025
Relative | 3.059 ± 0.057 | 3.179 ± 0.047 | 2.983 ± 0.036 | 3.308 ± 0.067^**^ | 3.330 ± 0.060^**^
R. Kidney
Absolute | 1.247 ± 0.012 | 1.302 ± 0.022 | 1.277 ± 0.026 | 1.296 ± 0.025 | 1.203 ± 0.018
Relative | 3.785 ± 0.044 | 3.873 ± 0.043 | 3.828 ± 0.049 | 3.991 ± 0.034^**^ | 4.016 ± 0.039^**^
Liver
Absolute | 12.450 ± 0.286 | 13.334 ± 0.278 | 13.146 ± 0.404 | 12.937 ± 0.336 | 11.713 ± 0.209
Relative | 37.761 ± 0.720 | 39.631 ± 0.396 | 39.347 ± 0.719 | 39.777 ± 0.421 | 39.104 ± 0.564
Lung
Absolute | 1.784 ± 0.126 | 1.925 ± 0.104 | 1.819 ± 0.106 | 1.747 ± 0.076 | 1.711 ± 0.099
Relative | 5.412 ± 0.378 | 5.717 ± 0.288 | 5.452 ± 0.303 | 5.362 ± 0.167 | 5.702 ± 0.309
R. Testis
Absolute | 1.411 ± 0.011 | 1.441 ± 0.022 | 1.444 ± 0.029 | 1.447 ± 0.028 | 1.386 ± 0.020
Relative | 4.290 ± 0.087 | 4.291 ± 0.072 | 4.328 ± 0.055 | 4.457 ± 0.054 | 4.630 ± 0.062^**^
Thymus
Absolute | 0.388 ± 0.035 | 0.369 ± 0.021 | 0.331 ± 0.012 | 0.311 ± 0.015^*^ | 0.314 ± 0.024^*^
Relative | 1.179 ± 0.111 | 1.099 ± 0.068 | 0.997 ± 0.047 | 0.954 ± 0.033 | 1.046 ± 0.079
Female
Necropsy body wt | 186 ± 3 | 191 ± 3 | 190 ± 4 | 193 ± 3 | 192 ± 4
Heart
Absolute | 0.729 ± 0.015 | 0.734 ± 0.013 | 0.755 ± 0.018 | 0.790 ± 0.017^**^ | 0.786 ± 0.008^**^
Relative | 3.927 ± 0.066 | 3.849 ± 0.044 | 3.963 ± 0.030 | 4.090 ± 0.034^*^ | 4.101 ± 0.060^*^
R. Kidney
Absolute | 0.747 ± 0.011 | 0.747 ± 0.015 | 0.791 ± 0.022 | 0.807 ± 0.019^*^ | 0.816 ± 0.011^**^
Relative | 4.023 ± 0.043 | 3.922 ± 0.074 | 4.152 ± 0.059 | 4.177 ± 0.058 | 4.254 ± 0.041^**^
Liver
Absolute | 6.845 ± 0.140 | 6.904 ± 0.198 | 7.138 ± 0.253 | 7.469 ± 0.213^*^ | 7.479 ± 0.168^*^
Relative | 36.878 ± 0.775 | 36.162 ± 0.683 | 37.391 ± 0.606 | 38.633 ± 0.581 | 38.943 ± 0.476^*^
Lung
Absolute | 1.164 ± 0.051 | 1.166 ± 0.062 | 1.267 ± 0.063 | 1.270 ± 0.069 | 1.255 ± 0.060
Relative | 6.287 ± 0.321 | 6.101 ± 0.275 | 6.640 ± 0.256 | 6.571 ± 0.324 | 6.540 ± 0.311
Thymus
Absolute | 0.260 ± 0.014 | 0.260 ± 0.017 | 0.285 ± 0.012 | 0.248 ± 0.014 | 0.259 ± 0.013
Relative | 1.403 ± 0.082 | 1.364 ± 0.082 | 1.495 ± 0.054 | 1.293 ± 0.085 | 1.349 ± 0.061

* Significantly different (P≤0.05) from the vehicle control group by Williams’ test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error); no data available for the 12 mg/kg groups due to 100% mortality.

TABLE G3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for B6C3F_1_ Mice in the 3-Week Dermal Study of Dicyclohexylcarbodiimide^a^

| Vehicle Control | 0.2 mg/animal | 0.6 mg/animal
Male
n | 5 | 5 | 5
Necropsy body wt | 28.8 ± 1.1 | 28.3 ± 0.5 | 26.0 ± 0.5*
Adrenal gland
Absolute | 0.010 ± 0.001 | 0.011 ± 0.001 | 0.024 ± 0.015
Relative | 0.348 ± 0.032 | 0.402 ± 0.026 | 0.959 ± 0.590
Heart
Absolute | 0.141 ± 0.004 | 0.144 ± 0.005 | 0.161 ± 0.004**
Relative | 4.912 ± 0.108 | 5.073 ± 0.127 | 6.194 ± 0.139**
R. Kidney
Absolute | 0.299 ± 0.010 | 0.291 ± 0.008 | 0.269 ± 0.005*
Relative | 10.405 ± 0.291 | 10.291 ± 0.217 | 10.371 ± 0.275
Liver
Absolute | 1.586 ± 0.048 | 1.668 ± 0.058 | 1.599 ± 0.040
Relative | 55.203 ± 0.835 | 58.891 ± 1.104* | 61.584 ± 1.327**
Lung
Absolute | 0.177 ± 0.006 | 0.191 ± 0.011 | 0.185 ± 0.005
Relative | 6.163 ± 0.268 | 6.749 ± 0.320 | 7.126 ± 0.252
R. Testis
Absolute | 0.125 ± 0.007 | 0.112 ± 0.005 | 0.109 ± 0.003
Relative | 4.343 ± 0.264 | 3.962 ± 0.148 | 4.187 ± 0.148
Thymus
Absolute | 0.050 ± 0.004 | 0.047 ± 0.003 | 0.028 ± 0.004**
Relative | 1.760 ± 0.173 | 1.649 ± 0.119 | 1.073 ± 0.162*
Female
n | 5 | 5 | 4
Necropsy body wt | 24.0 ± 0.5 | 23.9 ± 0.4 | 21.3 ± 0.8**
Adrenal gland
Absolute | 0.014 ± 0.001 | 0.013 ± 0.002 | 0.011 ± 0.001
Relative | 0.576 ± 0.041 | 0.532 ± 0.060 | 0.526 ± 0.038
Heart
Absolute | 0.132 ± 0.001 | 0.126 ± 0.003 | 0.148 ± 0.007*
Relative | 5.491 ± 0.094 | 5.265 ± 0.126 | 6.957 ± 0.212**
R. Kidney
Absolute | 0.213 ± 0.010 | 0.215 ± 0.006 | 0.209 ± 0.013
Relative | 8.880 ± 0.287 | 9.004 ± 0.281 | 9.790 ± 0.273
Liver
Absolute | 1.408 ± 0.040 | 1.378 ± 0.034 | 1.370 ± 0.098
Relative | 58.649 ± 0.708 | 57.585 ± 1.229 | 64.180 ± 2.380*
Lung
Absolute | 0.188 ± 0.006 | 0.194 ± 0.010 | 0.171 ± 0.009
Relative | 7.844 ± 0.351 | 8.132 ± 0.452 | 8.048 ± 0.531
Thymus
Absolute | 0.070 ± 0.003 | 0.080 ± 0.009 | 0.024 ± 0.005**
Relative | 2.906 ± 0.136 | 3.356 ± 0.371 | 1.099 ± 0.205**

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error); no data available for the 1.7, 5, and 15 mg/animal groups due to 100% mortality.

TABLE G4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for B6C3F_1_ Mice in the 13-Week Dermal Study of Dicyclohexylcarbodiimide^a^

| Vehicle Control | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
n | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 33.7 ± 0.6 | 33.1 ± 0.7 | 33.0 ± 0.5 | 31.5 ± 0.5^**^ | 30.4 ± 0.5^**^
Heart
Absolute | 0.154 ± 0.004 | 0.151 ± 0.006 | 0.161 ± 0.005 | 0.152 ± 0.003 | 0.158 ± 0.004
Relative | 4.577 ± 0.065 | 4.563 ± 0.135 | 4.884 ± 0.141 | 4.840 ± 0.091 | 5.191 ± 0.075^**^
R. Kidney
Absolute | 0.308 ± 0.005 | 0.322 ± 0.005 | 0.318 ± 0.010 | 0.281 ± 0.017 | 0.287 ± 0.010
Relative | 9.179 ± 0.193 | 9.788 ± 0.246 | 9.647 ± 0.280 | 8.937 ± 0.524 | 9.423 ± 0.234
Liver
Absolute | 1.578 ± 0.037 | 1.595 ± 0.061 | 1.645 ± 0.051 | 1.450 ± 0.034 | 1.566 ± 0.044
Relative | 46.954 ± 1.032 | 48.179 ± 1.401 | 49.919 ± 1.417 | 46.055 ± 0.435 | 51.567 ± 1.115^*^
Lung
Absolute | 0.311 ± 0.013 | 0.290 ± 0.014 | 0.264 ± 0.020^*^ | 0.241 ± 0.012^**^ | 0.206 ± 0.010^**^
Relative | 9.239 ± 0.361 | 8.754 ± 0.376 | 8.024 ± 0.615 | 7.677 ± 0.418^*^ | 6.759 ± 0.269^**^
R. Testis
Absolute | 0.121 ± 0.003 | 0.116 ± 0.003 | 0.124 ± 0.003 | 0.107 ± 0.010 | 0.117 ± 0.003
Relative | 3.606 ± 0.087 | 3.510 ± 0.081 | 3.780 ± 0.097 | 3.417 ± 0.333 | 3.858 ± 0.080
Thymus
Absolute | 0.043 ± 0.003 | 0.046 ± 0.003 | 0.043 ± 0.004 | 0.040 ± 0.002 | 0.040 ± 0.003
Relative | 1.289 ± 0.096 | 1.375 ± 0.085 | 1.286 ± 0.126 | 1.261 ± 0.083 | 1.321 ± 0.091
Female
Necropsy body wt | 28.8 ± 0.9 | 28.3 ± 1.1 | 27.8 ± 0.5 | 27.7 ± 0.3 | 26.5 ± 0.4
Heart
Absolute | 0.135 ± 0.003 | 0.134 ± 0.004 | 0.135 ± 0.002 | 0.149 ± 0.004^**^ | 0.148 ± 0.003^**^
Relative | 4.712 ± 0.126 | 4.745 ± 0.081 | 4.869 ± 0.079 | 5.391 ± 0.108^**^ | 5.591 ± 0.106^**^
R. Kidney
Absolute | 0.205 ± 0.004 | 0.202 ± 0.006 | 0.198 ± 0.004 | 0.204 ± 0.005 | 0.212 ± 0.004
Relative | 7.158 ± 0.143 | 7.177 ± 0.176 | 7.115 ± 0.159 | 7.383 ± 0.108 | 8.026 ± 0.140^**^
Liver
Absolute | 1.291 ± 0.015 | 1.366 ± 0.047 | 1.339 ± 0.033 | 1.380 ± 0.023 | 1.416 ± 0.027^**^
Relative | 45.012 ± 0.904 | 48.533 ± 1.516^*^ | 48.143 ± 0.813^*^ | 49.919 ± 0.739^**^ | 53.470 ± 0.612^**^
Lung
Absolute | 0.267 ± 0.018 | 0.268 ± 0.018 | 0.267 ± 0.012 | 0.279 ± 0.023 | 0.227 ± 0.017
Relative | 9.245 ± 0.474 | 9.422 ± 0.483 | 9.584 ± 0.392 | 10.077 ± 0.798 | 8.514 ± 0.488
Thymus
Absolute | 0.059 ± 0.002 | 0.059 ± 0.003 | 0.053 ± 0.005 | 0.048 ± 0.003 | 0.051 ± 0.004
Relative | 2.057 ± 0.104 | 2.104 ± 0.130 | 1.911 ± 0.175 | 1.733 ± 0.122 | 1.946 ± 0.181

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** Significantly different (P≤0.01) from the vehicle control group by Williams’ test

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error); no data available for the 24 mg/kg groups due to 100% mortality.

TABLE G5 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Female Tg.AC Hemizygous Mice in the 20-Week Dermal Study of Dicyclohexylcarbodiimide^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
n | 7 | 7 | 10 | 6 | 8 | 9
Necropsy body wt | 26.8 ± 1.5 | 27.7 ± 1.0 | 26.7 ± 0.7 | 27.5 ± 0.8 | 28.8 ± 0.9 | 27.4 ± 0.9
Heart
Absolute | 0.127 ± 0.005 | 0.121 ± 0.005 | 0.125 ± 0.003 | 0.126 ± 0.004 | 0.136 ± 0.004 | 0.139 ± 0.004
Relative | 4.778 ± 0.125 | 4.381 ± 0.087 | 4.702 ± 0.105 | 4.587 ± 0.093 | 4.719 ± 0.080 | 5.087 ± 0.198
R. Kidney
Absolute | 0.214 ± 0.010 | 0.207 ± 0.006 | 0.210 ± 0.005 | 0.221 ± 0.007 | 0.238 ± 0.008 | 0.251 ± 0.017*
Relative | 8.047 ± 0.210 | 7.500 ± 0.224 | 7.919 ± 0.217 | 8.045 ± 0.172 | 8.286 ± 0.249 | 9.158 ± 0.580
Liver
Absolute | 1.316 ± 0.091 | 1.444 ± 0.050 | 1.539 ± 0.084* | 1.562 ± 0.075* | 1.636 ± 0.064** | 1.638 ± 0.044**
Relative | 49.012 ± 1.366 | 52.350 ± 1.771 | 58.099 ± 3.589* | 56.844 ± 1.992* | 56.888 ± 2.098* | 59.911 ± 1.459**
Lung
Absolute | 0.211 ± 0.009 | 0.199 ± 0.014 | 0.204 ± 0.007 | 0.201 ± 0.010 | 0.197 ± 0.010 | 0.195 ± 0.007
Relative | 8.068 ± 0.632 | 7.188 ± 0.364 | 7.662 ± 0.299 | 7.330 ± 0.402 | 6.835 ± 0.284 | 7.139 ± 0.286
Thymus
Absolute | 0.037 ± 0.004^b^ | 0.043 ± 0.003 | 0.040 ± 0.002 | 0.040 ± 0.003 | 0.042 ± 0.005 | 0.040 ± 0.004
Relative | 1.464 ± 0.224^b^ | 1.564 ± 0.052 | 1.485 ± 0.053 | 1.467 ± 0.119 | 1.470 ± 0.167 | 1.472 ± 0.155

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** (P≤0.01)

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

b n = 6