# APPENDIX F CLINICAL PATHOLOGY RESULTS

TABLE F1 Hematology and Clinical Chemistry Data for F344/N Rats in the 13-Week Dermal Study of Dicyclohexylcarbodiimide^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Hematology
Automated hematocrit (%)
Day 3 | 40.9 ± 0.4 | 41.1 ± 0.7 | 42.2 ± 0.4 | 41.2 ± 0.6 | 40.4 ± 0.4 | 41.5 ± 0.8
Day 22 | 45.9 ± 0.4 | 45.0 ± 0.5 | 45.4 ± 0.6 | 44.6 ± 0.4 | 43.7 ± 0.3^**^ | 44.5 ± 0.5^*^
Week 13 | 44.1 ± 0.4 | 43.9 ± 0.7 | 44.4 ± 0.4 | 44.5 ± 0.3 | 44.5 ± 0.4 | —^b^
Manual hematocrit (%)
Day 3 | 44.3 ± 0.4 | 44.7 ± 0.8 | 45.4 ± 0.5 | 45.1 ± 0.6 | 45.5 ± 0.5 | 46.0 ± 0.7
Day 22 | 50.6 ± 0.6 | 49.8 ± 0.8 | 50.1 ± 0.6 | 48.8 ± 0.6 | 49.2 ± 0.4 | 49.5 ± 0.5
Week 13 | 46.8 ± 0.3 | 45.9 ± 0.6 | 46.6 ± 0.5 | 46.9 ± 0.4 | 46.4 ± 0.3 | —
Hemoglobin (g/dL)
Day 3 | 14.6 ± 0.1 | 14.7 ± 0.2 | 14.8 ± 0.1 | 14.7 ± 0.2 | 14.5 ± 0.2 | 14.6 ± 0.2
Day 22 | 16.2 ± 0.2 | 16.1 ± 0.2 | 16.1 ± 0.1 | 15.9 ± 0.1 | 15.5 ± 0.1^**^ | 15.6 ± 0.2^**^
Week 13 | 15.7 ± 0.1 | 15.5 ± 0.2 | 15.6 ± 0.1 | 15.7 ± 0.1 | 15.6 ± 0.1 | —
Erythrocytes (10^6^/μL)
Day 3 | 6.55 ± 0.08 | 6.66 ± 0.11 | 6.72 ± 0.05 | 6.66 ± 0.09 | 6.50 ± 0.08 | 6.63 ± 0.11
Day 22 | 7.66 ± 0.09 | 7.56 ± 0.08 | 7.60 ± 0.08 | 7.54 ± 0.08 | 7.38 ± 0.06^*^ | 7.63 ± 0.08
Week 13 | 8.70 ± 0.09 | 8.73 ± 0.12 | 8.81 ± 0.07 | 8.77 ± 0.06 | 8.83 ± 0.06 | —
Reticulocytes (10^6^/μL)
Day 3 | 0.41 ± 0.03 | 0.36 ± 0.03 | 0.33 ± 0.03 | 0.36 ± 0.03 | 0.36 ± 0.03 | 0.36 ± 0.03
Day 22 | 0.19 ± 0.01 | 0.18 ± 0.01 | 0.17 ± 0.01 | 0.18 ± 0.01 | 0.18 ± 0.02 | 0.14 ± 0.02
Week 13 | 0.18 ± 0.02 | 0.18 ± 0.01 | 0.16 ± 0.01 | 0.15 ± 0.01 | 0.15 ± 0.01 | —
Nucleated erythrocytes (10^3^/μL)
Day 3 | 1.70 ± 0.42 | 0.30 ± 0.15^*^ | 1.10 ± 0.31 | 0.50 ± 0.31 | 0.90 ± 0.35 | 0.80 ± 0.20
Day 22 | 0.60 ± 0.31 | 0.70 ± 0.34 | 0.70 ± 0.21 | 0.10 ± 0.10 | 0.60 ± 0.31 | 0.30 ± 0.30
Week 13 | 0.50 ± 0.27 | 0.20 ± 0.13 | 0.20 ± 0.13 | 0.40 ± 0.22 | 0.50 ± 0.22 | —
Mean cell volume (fL)
Day 3 | 62.5 ± 0.4 | 61.7 ± 0.4 | 62.8 ± 0.3 | 61.9 ± 0.4 | 62.2 ± 0.5 | 62.5 ± 0.4
Day 22 | 59.9 ± 0.4 | 59.6 ± 0.2 | 59.8 ± 0.3 | 59.2 ± 0.5 | 59.3 ± 0.3 | 58.4 ± 0.2^**^
Week 13 | 50.7 ± 0.2 | 50.3 ± 0.2 | 50.4 ± 0.2 | 50.7 ± 0.1 | 50.4 ± 0.1 | —
Mean cell hemoglobin (pg)
Day 3 | 22.3 ± 0.1 | 22.1 ± 0.1 | 22.0 ± 0.1 | 22.1 ± 0.2 | 22.3 ± 0.1 | 22.0 ± 0.2
Day 22 | 21.1 ± 0.2 | 21.3 ± 0.1 | 21.2 ± 0.2 | 21.1 ± 0.1 | 21.0 ± 0.1 | 20.4 ± 0.1^**^
Week 13 | 18.0 ± 0.1 | 17.8 ± 0.1 | 17.7 ± 0.1 | 17.9 ± 0.1 | 17.7 ± 0.1 | —
Mean cell hemoglobin concentration (g/dL)
Day 3 | 35.7 ± 0.2 | 35.8 ± 0.3 | 35.0 ± 0.2 | 35.7 ± 0.3 | 35.9 ± 0.2 | 35.3 ± 0.3
Day 22 | 35.2 ± 0.2 | 35.7 ± 0.2 | 35.4 ± 0.3 | 35.6 ± 0.2 | 35.4 ± 0.2 | 35.0 ± 0.2
Week 13 | 35.5 ± 0.2 | 35.3 ± 0.3 | 35.1 ± 0.2 | 35.4 ± 0.2 | 35.2 ± 0.2 | —
Platelets (10^3^/μL)
Day 3 | 896.1 ± 37.5 | 826.5 ± 30.3 | 795.2 ± 24.9 | 841.3 ± 39.1 | 827.5 ± 23.1 | 815.1 ± 23.8
Day 22 | 766.3 ± 20.5 | 775.1 ± 14.2 | 778.5 ± 18.2 | 761.6 ± 39.1 | 804.2 ± 15.3 | 788.0 ± 26.9
Week 13 | 759.8 ± 17.2 | 720.2 ± 26.6 | 708.4 ± 22.6 | 730.5 ± 27.5 | 777.2 ± 22.2 | —
Leukocytes (10^3^/μL)
Day 3 | 10.85 ± 0.23 | 10.06 ± 0.38 | 9.87 ± 0.34 | 10.24 ± 0.47 | 10.82 ± 0.27 | 12.35 ± 0.35
Day 22 | 9.39 ± 0.24 | 8.76 ± 0.61 | 9.88 ± 0.67 | 10.80 ± 0.83 | 19.94 ± 1.54^**^ | 24.65 ± 1.77^**^
Week 13 | 8.26 ± 0.60 | 7.88 ± 0.45 | 7.20 ± 0.59 | 9.19 ± 0.93 | 9.63 ± 0.52 | —
Segmented neutrophils (10^3^/μL)
Day 3 | 1.05 ± 0.13 | 0.97 ± 0.08 | 1.16 ± 0.11 | 0.99 ± 0.13 | 1.74 ± 0.21^*^ | 2.47 ± 0.18^**^
Day 22 | 0.96 ± 0.09 | 1.24 ± 0.14 | 1.15 ± 0.12 | 2.14 ± 0.31^**^ | 9.71 ± 1.00^**^ | 14.24 ± 1.24^**^
Week 13 | 1.18 ± 0.10 | 1.14 ± 0.18 | 1.02 ± 0.16 | 1.87 ± 0.65 | 1.80 ± 0.25 | —
Bands (10^3^/μL)
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.01 ± 0.01 | 0.00 ± 0.00 | 0.01 ± 0.01 | 0.05 ± 0.02
Day 22 | 0.00 ± 0.00 | 0.02 ± 0.01 | 0.03 ± 0.01 | 0.13 ± 0.05^**^ | 0.73 ± 0.12^**^ | 0.75 ± 0.06^**^
Week 13 | 0.00 ± 0.00 | 0.01 ± 0.01 | 0.02 ± 0.02 | 0.01 ± 0.01 | 0.02 ± 0.02 | —
Lymphocytes (10^3^/μL)
Day 3 | 9.53 ± 0.16 | 8.93 ± 0.37 | 8.38 ± 0.30 | 9.05 ± 0.45 | 8.81 ± 0.24 | 9.50 ± 0.42
Day 22 | 8.16 ± 0.25 | 7.20 ± 0.51 | 8.41 ± 0.65 | 8.24 ± 0.65 | 8.85 ± 0.66 | 8.78 ± 1.15
Week 13 | 6.80 ± 0.57 | 6.39 ± 0.30 | 5.90 ± 0.47 | 7.13 ± 0.51 | 7.49 ± 0.33 | —
Atypical lymphocytes (10^3^/μL)
Day 3 | 0.02 ± 0.01 | 0.00 ± 0.00 | 0.01 ± 0.01 | 0.02 ± 0.02 | 0.00 ± 0.00 | 0.01 ± 0.01
Day 22 | 0.01 ± 0.01^c^ | 0.02 ± 0.01 | 0.01 ± 0.01 | 0.01 ± 0.01 | 0.00 ± 0.00 | 0.03 ± 0.03
Week 13 | 0.03 ± 0.01 | 0.04 ± 0.03 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.05 ± 0.02 | —
Monocytes (10^3^/μL)
Day 3 | 0.22 ± 0.04 | 0.12 ± 0.03 | 0.25 ± 0.04 | 0.16 ± 0.06 | 0.23 ± 0.05 | 0.29 ± 0.06
Day 22 | 0.22 ± 0.03 | 0.24 ± 0.04 | 0.24 ± 0.04 | 0.22 ± 0.05 | 0.58 ± 0.21 | 0.62 ± 0.11^**^
Week 13 | 0.19 ± 0.04 | 0.22 ± 0.07 | 0.15 ± 0.06 | 0.16 ± 0.04 | 0.19 ± 0.05 | —
Eosinophils (10^3^/μL)
Day 3 | 0.03 ± 0.02 | 0.03 ± 0.02 | 0.06 ± 0.02 | 0.02 ± 0.01 | 0.03 ± 0.02 | 0.04 ± 0.02
Day 22 | 0.04 ± 0.02 | 0.04 ± 0.01 | 0.04 ± 0.02 | 0.06 ± 0.03 | 0.07 ± 0.04 | 0.24 ± 0.06^**^
Week 13 | 0.06 ± 0.02 | 0.08 ± 0.03 | 0.11 ± 0.04 | 0.02 ± 0.02 | 0.08 ± 0.04 | —
Clinical Chemistry
Urea nitrogen (mg/dL)
Day 3 | 23.9 ± 0.9 | 22.9 ± 0.6 | 22.8 ± 0.6 | 23.7 ± 0.7 | 22.1 ± 0.4 | 21.4 ± 0.7
Day 22 | 23.2 ± 0.6 | 22.9 ± 0.7 | 22.8 ± 0.6 | 23.4 ± 0.5 | 21.4 ± 0.5 | 21.1 ± 0.7
Week 13 | 19.9 ± 0.5 | 19.1 ± 0.3 | 19.7 ± 0.4 | 18.8 ± 0.9 | 19.8 ± 0.3 | —
Creatinine (mg/dL)
Day 3 | 0.26 ± 0.02 | 0.27 ± 0.02 | 0.24 ± 0.02 | 0.28 ± 0.02 | 0.23 ± 0.02 | 0.23 ± 0.02
Day 22 | 0.33 ± 0.02 | 0.28 ± 0.01 | 0.28 ± 0.01 | 0.26 ± 0.02^*^ | 0.30 ± 0.02 | 0.28 ± 0.01
Week 13 | 0.36 ± 0.02 | 0.38 ± 0.02 | 0.35 ± 0.02 | 0.35 ± 0.02 | 0.36 ± 0.02 | —
Total protein (g/dL)
Day 3 | 5.7 ± 0.1 | 5.7 ± 0.1 | 5.8 ± 0.1 | 5.8 ± 0.1 | 5.6 ± 0.0 | 5.6 ± 0.1
Day 22 | 6.2 ± 0.1 | 6.1 ± 0.1 | 6.0 ± 0.1 | 6.1 ± 0.1 | 6.0 ± 0.1 | 5.8 ± 0.1^**^
Week 13 | 6.9 ± 0.1 | 6.9 ± 0.1 | 7.1 ± 0.1 | 6.6 ± 0.3 | 6.8 ± 0.1 | —
Albumin (g/dL)
Day 3 | 4.6 ± 0.1 | 4.7 ± 0.1 | 4.7 ± 0.1 | 4.7 ± 0.0 | 4.6 ± 0.0 | 4.5 ± 0.0
Day 22 | 4.8 ± 0.0 | 4.8 ± 0.0 | 4.7 ± 0.1 | 4.6 ± 0.1^*^ | 4.3 ± 0.0^**^ | 4.0 ± 0.1^**^
Week 13 | 5.0 ± 0.1 | 4.9 ± 0.1 | 5.0 ± 0.0 | 4.5 ± 0.2^*^ | 4.7 ± 0.1^**^ | —
Alanine aminotransferase (IU/L)
Day 3 | 51 ± 1 | 49 ± 1 | 53 ± 1 | 53 ± 1 | 61 ± 2^**^ | 76 ± 3^**^
Day 22 | 53 ± 2 | 54 ± 1 | 52 ± 2 | 62 ± 1^**^ | 68 ± 3^**^ | 77 ± 4^**^
Week 13 | 57 ± 3 | 60 ± 2 | 63 ± 3 | 63 ± 5 | 68 ± 4 | —
Alkaline phosphatase (IU/L)
Day 3 | 762 ± 26 | 752 ± 20 | 761 ± 22 | 767 ± 11 | 736 ± 16 | 728 ± 12
Day 22 | 520 ± 9 | 532 ± 10 | 501 ± 13 | 527 ± 11 | 462 ± 12^**^ | 442 ± 15^**^
Week 13 | 262 ± 5 | 276 ± 12 | 275 ± 3 | 259 ± 20 | 290 ± 6^*^ | —
Creatine kinase (IU/L)
Day 3 | 581 ± 54 | 665 ± 63 | 565 ± 82 | 602 ± 42 | 570 ± 56 | 582 ± 66
Day 22 | 535 ± 76 | 476 ± 105 | 504 ± 95 | 284 ± 25^*^,^c^ | 347 ± 49 | 360 ± 42
Week 13 | 304 ± 49 | 192 ± 32 | 268 ± 55 | 236 ± 46 | 265 ± 38 | —
Sorbitol dehydrogenase (IU/L)
Day 3 | 21 ± 1 | 20 ± 2 | 23 ± 2 | 23 ± 1 | 20 ± 2 | 22 ± 2
Day 22 | 24 ± 2 | 28 ± 2 | 22 ± 2 | 31 ± 1 | 26 ± 2 | 24 ± 2
Week 13 | 22 ± 1 | 22 ± 2 | 24 ± 1 | 22 ± 1 | 20 ± 1 | —
Bile acids (μmol/L)
Day 3 | 25.0 ± 3.2 | 23.2 ± 3.1 | 31.8 ± 6.0 | 23.4 ± 2.6 | 37.0 ± 6.3 | 45.2 ± 5.3
Day 22 | 26.9 ± 3.4 | 22.8 ± 2.0 | 26.6 ± 2.8 | 25.9 ± 2.5 | 26.2 ± 4.3 | 20.3 ± 1.8
Week 13 | 22.0 ± 2.9 | 15.8 ± 1.7 | 17.2 ± 0.9 | 18.4 ± 1.2 | 20.2 ± 2.3 | —
Female
Hematology
Automated hematocrit (%)
Day 3 | 42.8 ± 0.6 | 43.2 ± 0.4 | 43.3 ± 0.4 | 43.3 ± 0.5 | 43.7 ± 0.3 | 43.3 ± 0.5
Day 22 | 46.7 ± 0.4 | 46.9 ± 0.3 | 47.2 ± 0.3 | 47.1 ± 0.8 | 45.5 ± 0.3 | 46.1 ± 0.5
Week 13 | 45.6 ± 0.3 | 44.6 ± 0.6 | 45.2 ± 0.4 | 43.3 ± 0.4^**^ | 43.0 ± 0.5^**^ | —
Manual hematocrit (%)
Day 3 | 45.6 ± 0.9 | 45.3 ± 0.5 | 46.5 ± 0.5 | 46.5 ± 0.7 | 46.3 ± 0.6 | 46.0 ± 0.7
Day 22 | 48.5 ± 0.4 | 49.3 ± 0.4 | 49.3 ± 0.5 | 49.1 ± 1.0 | 48.3 ± 0.4 | 48.7 ± 0.4
Week 13 | 46.7 ± 0.3 | 45.9 ± 0.5 | 46.8 ± 0.2 | 45.7 ± 0.4 | 45.1 ± 0.5^*^ | —
Hemoglobin (g/dL)
Day 3 | 15.2 ± 0.2 | 15.3 ± 0.1 | 15.3 ± 0.1 | 15.3 ± 0.1 | 15.5 ± 0.1 | 15.3 ± 0.2
Day 22 | 16.2 ± 0.2 | 16.5 ± 0.1 | 16.4 ± 0.1 | 16.3 ± 0.3 | 15.9 ± 0.1 | 15.7 ± 0.1^*^
Week 13 | 15.8 ± 0.1 | 15.6 ± 0.2 | 15.8 ± 0.1 | 15.3 ± 0.2^**^ | 15.1 ± 0.2^**^ | —
Erythrocytes (10^6^/μL)
Day 3 | 6.94 ± 0.09 | 7.02 ± 0.06 | 7.03 ± 0.07 | 7.03 ± 0.08 | 7.09 ± 0.07 | 7.01 ± 0.09
Day 22 | 7.60 ± 0.06 | 7.64 ± 0.05 | 7.66 ± 0.06 | 7.69 ± 0.13 | 7.52 ± 0.05 | 7.67 ± 0.12
Week 13 | 8.08 ± 0.06 | 7.92 ± 0.10 | 8.03 ± 0.06 | 7.68 ± 0.07^**^ | 7.74 ± 0.09^**^ | —
Reticulocytes (10^6^/μL)
Day 3 | 0.25 ± 0.03 | 0.33 ± 0.03 | 0.29 ± 0.03 | 0.29 ± 0.03 | 0.32 ± 0.03 | 0.24 ± 0.03
Day 22 | 0.20 ± 0.02 | 0.13 ± 0.01^**^ | 0.12 ± 0.01^**^ | 0.14 ± 0.01 | 0.17 ± 0.02 | 0.17 ± 0.02
Week 13 | 0.16 ± 0.01 | 0.15 ± 0.01 | 0.14 ± 0.01 | 0.14 ± 0.01 | 0.14 ± 0.01 | —
Nucleated erythrocytes (10^3^/μL)
Day 3 | 0.70 ± 0.21 | 0.60 ± 0.22 | 0.60 ± 0.22 | 0.20 ± 0.13 | 0.70 ± 0.26 | 0.80 ± 0.13
Day 22 | 0.70 ± 0.21 | 0.70 ± 0.30 | 0.40 ± 0.16 | 0.50 ± 0.17 | 0.40 ± 0.22 | 0.10 ± 0.10
Week 13 | 1.10 ± 0.28 | 0.70 ± 0.34 | 0.70 ± 0.34 | 0.80 ± 0.36 | 0.10 ± 0.10^*^ | —
Mean cell volume (fL)
Day 3 | 61.6 ± 0.2 | 61.5 ± 0.1 | 61.6 ± 0.2 | 61.6 ± 0.2 | 61.6 ± 0.2 | 61.8 ± 0.3
Day 22 | 61.4 ± 0.3 | 61.4 ± 0.2 | 61.7 ± 0.2 | 61.2 ± 0.2 | 60.6 ± 0.2^*^ | 60.1 ± 0.3^**^
Week 13 | 56.3 ± 0.1 | 56.3 ± 0.1 | 56.3 ± 0.1 | 56.4 ± 0.1 | 55.6 ± 0.2^*^ | —
Mean cell hemoglobin (pg)
Day 3 | 21.9 ± 0.1 | 21.7 ± 0.1 | 21.8 ± 0.1 | 21.7 ± 0.1 | 21.8 ± 0.1 | 21.9 ±0.1
Day 22 | 21.3 ± 0.1 | 21.6 ± 0.1 | 21.5 ± 0.1 | 21.2 ± 0.1 | 21.1 ± 0.1 | 20.5 ± 0.2^**^
Week 13 | 19.6 ± 0.1 | 19.7 ± 0.1 | 19.7 ± 0.1 | 19.9 ± 0.1 | 19.5 ± 0.1 | —
Mean cell hemoglobin concentration (g/dL)
Day 3 | 35.5 ± 0.1 | 35.3 ± 0.2 | 35.4 ± 0.1 | 35.3 ± 0.1 | 35.4 ± 0.2 | 35.4 ± 0.2
Day 22 | 34.8 ± 0.2 | 35.2 ± 0.1 | 34.8 ± 0.1 | 34.7 ± 0.2 | 34.8 ± 0.2 | 34.2 ± 0.2
Week 13 | 34.8 ± 0.2 | 35.0 ± 0.2 | 35.0 ± 0.2 | 35.3 ± 0.2 | 35.1 ± 0.2 | —
Platelets (10^3^/μL)
Day 3 | 785.9 ± 18.3 | 797.6 ± 18.7 | 788.3 ± 21.5 | 781.4 ± 26.3 | 833.7 ± 32.6 | 808.1 ± 19.5
Day 22 | 731.2 ± 21.5 | 786.7 ± 19.0 | 747.8 ± 22.5 | 673.8 ± 36.3 | 701.1 ± 16.4 | 707.3 ± 21.4
Week 13 | 649.0 ± 25.6 | 653.7 ± 14.2 | 631.7 ± 29.4 | 710.4 ± 26.7^*^ | 718.9 ± 25.1^*^ | —
Leukocytes (10^3^/μL)
Day 3 | 10.79 ± 0.49 | 11.49 ± 0.33 | 11.33 ± 0.41 | 11.44 ± 0.34 | 11.78 ± 0.46 | 13.31 ± 0.62^**^
Day 22 | 7.62 ± 0.18 | 8.44 ± 0.67 | 8.07 ± 0.47 | 8.61 ± 0.75 | 14.50 ± 0.82^**^ | 20.13 ± 1.22^**^
Week 13 | 6.60 ± 0.31 | 6.37 ± 0.82 | 7.63 ± 0.73 | 6.74 ± 0.61 | 9.79 ± 1.18 | —
Segmented neutrophils (10^3^/μL)
Day 3 | 0.90 ± 0.11 | 1.34 ± 0.11^*^ | 1.11 ± 0.15 | 1.21 ± 0.16 | 1.77 ± 0.25^**^ | 3.21 ± 0.30^**^
Day 22 | 1.12 ± 0.12 | 1.05 ± 0.16 | 1.26 ± 0.19 | 1.50 ± 0.27 | 6.06 ± 0.62^**^ | 9.75 ± 0.86^**^
Week 13 | 1.07 ± 0.15 | 0.91 ± 0.18 | 1.08 ± 0.22 | 1.17 ± 0.21 | 2.37 ± 0.46^*^ | —
Bands (10^3^/μL)
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.01 ± 0.01 | 0.00 ± 0.00 | 0.02 ± 0.02 | 0.01 ± 0.01
Day 22 | 0.03 ± 0.01 | 0.03 ± 0.02 | 0.00 ± 0.00 | 0.05 ± 0.02 | 0.16 ± 0.07 | 0.19 ± 0.06
Week 13 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.01 ± 0.01 | —
Lymphocytes (10^3^/μL)
Day 3 | 9.72 ± 0.45 | 9.92 ± 0.31 | 9.87 ± 0.36 | 9.99 ± 0.31 | 9.70 ± 0.45 | 9.71 ± 0.50
Day 22 | 6.33 ± 0.21 | 7.14 ± 0.58 | 6.64 ± 0.38 | 6.68 ± 0.52 | 7.80 ± 0.24^**^ | 9.59 ± 0.70^**^
Week 13 | 5.29 ± 0.26 | 5.18 ± 0.62 | 6.23 ± 0.61 | 5.39 ± 0.56 | 7.07 ± 0.81 | —
Atypical lymphocytes (10^3^/μL)
Day 3 | 0.01 ± 0.01 | 0.01 ± 0.01 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.03 ± 0.02
Day 22 | 0.02 ± 0.01 | 0.04 ± 0.01 | 0.01 ± 0.01 | 0.08 ± 0.03 | 0.08 ± 0.04 | 0.06 ± 0.03
Week 13 | 0.01 ± 0.01 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | —
Monocytes (10^3^/μL)
Day 3 | 0.14 ± 0.03 | 0.18 ± 0.06 | 0.26 ± 0.05 | 0.21 ± 0.04 | 0.25 ± 0.05 | 0.26 ± 0.06
Day 22 | 0.09 ± 0.02 | 0.08 ± 0.02 | 0.11 ± 0.03 | 0.15 ± 0.04 | 0.25 ± 0.06^*^ | 0.31 ± 0.10
Week 13 | 0.20 ± 0.04 | 0.23 ± 0.08 | 0.28 ± 0.04 | 0.15 ± 0.03 | 0.25 ± 0.08 | —
Eosinophils (10^3^/μL)
Day 3 | 0.02 ± 0.02 | 0.03 ± 0.02 | 0.08 ± 0.03 | 0.04 ± 0.03 | 0.04 ± 0.02 | 0.10 ± 0.04
Day 22 | 0.03 ± 0.02 | 0.10 ± 0.02^*^ | 0.05 ± 0.03 | 0.15 ± 0.05^**^ | 0.16 ± 0.05^*^ | 0.23 ± 0.07^*^
Week 13 | 0.04 ± 0.02 | 0.05 ± 0.02 | 0.04 ± 0.02 | 0.02 ± 0.01 | 0.09 ± 0.02 | —
Clinical Chemistry
Urea nitrogen (mg/dL)
Day 3 | 24.6 ± 0.9 | 23.1 ± 0.5 | 24.4 ± 0.6 | 23.5 ± 1.0 | 24.2 ± 0.7 | 24.1 ± 0.7
Day 22 | 26.5 ± 0.8 | 25.9 ± 0.6 | 25.5 ± 0.6 | 25.3 ± 0.8 | 24.4 ± 0.6^*^ | 24.3 ± 0.6
Week 13 | 23.4 ± 0.7 | 23.0 ± 0.5 | 23.1 ± 0.7 | 22.1 ± 0.7 | 22.0 ± 0.4 | —
Creatinine (mg/dL)
Day 3 | 0.25 ± 0.02 | 0.24 ± 0.02 | 0.28 ± 0.01 | 0.28 ± 0.01 | 0.30 ± 0.00^*^ | 0.29 ± 0.02^*^
Day 22 | 0.27 ± 0.02 | 0.26 ± 0.02 | 0.28 ± 0.01 | 0.24 ± 0.02 | 0.29 ± 0.01 | 0.22 ± 0.01
Week 13 | 0.32 ± 0.01 | 0.30 ± 0.00 | 0.32 ± 0.01 | 0.31 ± 0.01 | 0.30 ± 0.00 | —
Total protein (g/dL)
Day 3 | 5.7 ± 0.1 | 5.7 ± 0.1 | 5.7 ± 0.1 | 5.7 ± 0.1 | 5.8 ± 0.1 | 5.8 ± 0.1
Day 22 | 5.8 ± 0.1 | 5.8 ± 0.1 | 5.8 ± 0.1 | 5.8 ± 0.1 | 5.6 ± 0.1 | 5.5 ± 0.1
Week 13 | 7.0 ± 0.1 | 6.6 ± 0.1 | 6.7 ± 0.1 | 6.8 ± 0.1 | 6.9 ± 0.1 | —
Albumin (g/dL)
Day 3 | 4.8 ± 0.0 | 4.8 ± 0.1 | 4.7 ± 0.1 | 4.7 ± 0.1 | 4.7 ± 0.1 | 4.7 ± 0.1
Day 22 | 4.7 ± 0.0 | 4.7 ± 0.1 | 4.6 ± 0.0 | 4.7 ± 0.1 | 4.1 ± 0.1^**^ | 3.8 ± 0.1^**^
Week 13 | 4.8 ± 0.1 | 4.8 ± 0.1 | 4.7 ± 0.1 | 4.7 ± 0.1 | 4.5 ± 0.1^**^ | —
Alanine aminotransferase (IU/L)
Day 3 | 46 ± 1 | 45 ± 1 | 47 ± 1 | 44 ± 1 | 56 ± 2^**^ | 67 ± 4^**^
Day 22 | 42 ± 1 | 44 ± 2 | 47 ± 2^*^ | 49 ± 2^*^ | 56 ± 2^**^ | 62 ± 2^**^
Week 13 | 55 ± 4 | 59 ± 4 | 63 ± 4 | 59 ± 3 | 64 ± 6 | —
Alkaline phosphatase (IU/L)
Day 3 | 643 ± 17 | 649 ± 9 | 633 ± 11 | 628 ± 9 | 638 ± 15 | 571 ± 53
Day 22 | 483 ± 13 | 489 ± 9 | 446 ± 8^*^ | 473 ± 15 | 404 ± 12^**^ | 384 ± 22^**^
Week 13 | 301 ± 8 | 292 ± 8 | 311 ± 8 | 293 ± 4 | 311 ± 13 | —
Creatine kinase (IU/L)
Day 3 | 343 ± 51 | 352 ± 35 | 332 ± 46 | 288 ± 42 | 309 ± 32 | 351 ± 38
Day 22 | 361 ± 57 | 261 ± 17 | 476 ± 85 | 284 ± 27 | 395 ± 46 | 337 ± 26
Week 13 | 294 ± 37 | 256 ± 35 | 318 ± 61 | 245 ± 36 | 223 ± 30 | —
Sorbitol dehydrogenase (IU/L)
Day 3 | 22 ± 1 | 23 ± 1 | 21 ± 1 | 22 ± 1 | 22 ± 1 | 22 ± 1
Day 22 | 24 ± 1 | 26 ± 1 | 24 ± 1 | 23 ± 1 | 22 ± 1 | 19 ± 1^**^
Week 13 | 25 ± 2 | 27 ± 1 | 26 ± 1 | 26 ± 1 | 24 ± 1 | —
Bile acids (μmol/L)
Day 3 | 15.2 ± 2.4 | 25.1 ± 5.5 | 20.3 ± 5.6 | 18.7 ± 3.3 | 26.1 ± 5.4 | 20.0 ± 4.0
Day 22 | 15.5 ± 1.2 | 19.3 ± 2.5 | 24.2 ± 2.7 | 17.6 ± 2.4 | 22.0 ± 3.4 | 23.3 ± 8.1
Week 13 | 18.1 ± 1.8 | 15.6 ± 1.4 | 23.8 ± 5.4 | 17.8 ± 2.9 | 19.0 ± 2.4 | —

* Significantly different (P≤0.05) from the vehicle control group by Dunn’s or Shirley’s test

** P≤0.01

a Mean ± standard error. Statistical tests were performed on unrounded data.

b No data available due to 100% mortality

c n=9

TABLE F2 Hematology Data for B6C3F_1_ Mice in the 13-Week Dermal Study of Dicyclohexylcarbodiimide^a^

| Vehicle Control | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
n | 10 | 10 | 10 | 10 | 10
Male
Automated hematocrit (%) | 52.9 ± 0.7 | 52.0 ± 0.7 | 51.1 ± 0.8 | 50.0 ± 0.6^*^ | 47.8 ± 0.6^**^
Manual hematocrit (%) | 53.0 ± 0.6 | 51.4 ± 0.5^*^ | 50.4 ± 0.6^**^ | 50.2 ± 0.6^**^ | 48.3 ± 0.7^**^
Hemoglobin (g/dL) | 16.9 ± 0.1 | 16.6 ± 0.2 | 16.4 ± 0.2^*^ | 16.1 ± 0.1^**^ | 15.3 ± 0.2^**^
Erythrocytes (10^6^/μL) | 10.39 ± 0.13 | 10.23 ± 0.15 | 10.03 ± 0.15 | 9.89 ± 0.15 | 9.44 ± 0.11^**^
Reticulocytes (10^6^/μL) | 0.20 ± 0.01 | 0.18 ± 0.01 | 0.19 ± 0.01 | 0.18 ± 0.01 | 0.18 ± 0.02
Nucleated erythrocytes (10^3^/μL) | 0.10 ± 0.10 | 0.10 ± 0.10 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 51.0 ± 0.2 | 50.9 ± 0.2 | 50.9 ± 0.2 | 50.6 ± 0.3 | 50.6 ± 0.2
Mean cell hemoglobin (pg) | 16.3 ± 0.2 | 16.3 ± 0.1 | 16.3 ± 0.1 | 16.3 ± 0.1 | 16.2 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 31.9 ± 0.3 | 32.0 ± 0.2 | 32.1 ± 0.2 | 32.2 ± 0.2 | 32.0 ± 0.2
Platelets (10^3^/μL) | 637.2 ± 25.7 | 708.9 ± 36.1 | 664.6 ± 26.3 | 737.2 ± 15.0^*^ | 830.8 ± 25.3^**^
Leukocytes (10^3^/μL) | 4.73 ± 0.45 | 5.98 ± 0.64 | 4.99 ± 0.39 | 6.11 ± 0.69 | 7.80 ± 0.63^**^
Segmented neutrophils (10^3^/μL) | 0.41 ± 0.05 | 0.88 ± 0.25 | 0.52 ± 0.10 | 0.74 ± 0.17 | 1.27 ± 0.22^**^
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.02 ± 0.01^*^
Lymphocytes (10^3^/μL) | 4.24 ± 0.41 | 4.99 ± 0.46 | 4.38 ± 0.32 | 5.22 ± 0.55 | 6.34 ± 0.51^**^
Monocytes (10^3^/μL) | 0.05 ± 0.01 | 0.08 ± 0.02 | 0.06 ± 0.02 | 0.11 ± 0.03 | 0.16 ± 0.05
Eosinophils (10^3^/μL) | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.04 ± 0.01 | 0.02 ± 0.01
Female
Automated hematocrit (%) | 50.9 ± 0.7 | 50.8 ± 0.6 | 50.7 ± 0.6 | 48.7 ± 0.8 | 48.1 ± 0.6^*^
Manual hematocrit (%) | 51.1 ± 0.7 | 51.2 ± 0.4 | 51.4 ± 0.6 | 49.0 ± 0.7 | 49.0 ± 0.4
Hemoglobin (g/dL) | 16.3 ± 0.2 | 16.3 ± 0.1 | 16.3 ± 0.1 | 15.8 ± 0.2 | 15.7 ± 0.1^*^
Erythrocytes (10^6^/μL) | 9.96 ± 0.14 | 9.92 ± 0.12 | 9.93 ± 0.12 | 9.55 ± 0.17 | 9.40 ± 0.11^*^
Reticulocytes (10^6^/μL) | 0.19 ± 0.01 | 0.25 ± 0.02 | 0.20 ± 0.02 | 0.24 ± 0.02 | 0.20 ± 0.02
Nucleated erythrocytes (10^3^/μL) | 0.10 ± 0.10 | 0.00 ± 0.00 | 0.10 ± 0.10 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 51.1 ± 0.1 | 51.3 ± 0.1 | 51.1 ± 0.2 | 51.0 ± 0.1 | 51.2 ± 0.2
Mean cell hemoglobin (pg) | 16.4 ± 0.1 | 16.4 ± 0.1 | 16.4 ± 0.1 | 16.5 ± 0.1 | 16.7 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 32.0 ± 0.2 | 32.1 ± 0.2 | 32.1 ± 0.1 | 32.4 ± 0.2 | 32.6 ± 0.2
Platelets (10^3^/μL) | 607.9 ± 34.2 | 637.2 ± 25.6 | 616.5 ± 31.1 | 686.9 ± 36.9 | 751.2 ± 39.4^*^
Leukocytes (10^3^/μL) | 4.05 ± 0.39 | 4.16 ± 0.26 | 4.38 ± 0.28 | 4.42 ± 0.25 | 5.76 ± 0.45^**^
Segmented neutrophils (10^3^/μL) | 0.36 ± 0.03 | 0.43 ± 0.05 | 0.35 ± 0.04 | 0.50 ± 0.08 | 1.05 ± 0.23^**^
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.01 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.02 ± 0.01
Lymphocytes (10^3^/μL) | 3.59 ± 0.36 | 3.64 ± 0.26 | 3.92 ± 0.27 | 3.80 ± 0.25 | 4.52 ± 0.26
Atypical lymphocytes (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.01 ± 0.01 | 0.02 ± 0.01
Monocytes (10^3^/μL) | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.08 ± 0.01 | 0.06 ± 0.01 | 0.11 ± 0.02
Eosinophils (10^3^/μL) | 0.04 ± 0.01 | 0.03 ± 0.01 | 0.02 ± 0.01 | 0.05 ± 0.01 | 0.05 ± 0.01

* Significantly different (P≤0.05) from the vehicle control group by Dunn’s or Shirley’s test

** Significantly different (P≤0.01) from the vehicle control group by Shirley’s test

a Mean ± standard error. Statistical tests were performed on unrounded data. No data available for the 24 mg/kg groups due to 100% mortality.