# APPENDIX E GENETIC TOXICOLOGY

TABLE E1 Mutagenicity of Dicyclohexylcarbodiimide in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Revertants/Plate^b^
Strain | Dose (μg/plate) | −S9 | | + hamster S9 | | + rat S9
Strain | Dose (μg/plate) | Trial 1 | Trial 2 | 10% | 30% | 10% | 30%
TA100 | 0 | 84 ± 1.0 | 97 ± 5.5 | 105 ± 8.1 | 92 ± 1.9 | 98 ± 7.5 | 107 ± 5.4
| 0.1 | | 87 ± 3.8
| 0.3 | 86 ± 3.7 | 97 ± 6.7
| 1 | 85 ± 2.3 | 100 ± 3.8
| 3 | 88 ± 6.8 | 92 ± 6.1 | 95 ± 1.5 | | 103 ± 2.9
| 10 | 85 ± 0.0 | 62 ± 3.8^c^ | 89 ± 1.2 | 101 ± 0.3 | 98 ± 4.3 | 102 ± 5.2
| 33 | Toxic | | 88 ± 7.9 | 90 ± 0.3 | 94 ± 4.3 | 112 ± 6.7
| 100 | | | 94 ± 3.2 | 88 ± 5.8 | 83 ± 2.5 | 97 ± 2.8
| 333 | | | 57 ± 5.4^c^ | 87 ± 0.9 | 22 ± 11.7^c^ | 86 ± 1.9
| 666 | | | | 8 ± 5.7^c^ | | 39 ± 5.8^c^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control^d^ | | 829 ± 11.4 | 792 ± 19.7 | 522 ± 26.4 | 612 ± 11.8 | 428 ± 13.5 | 492 ± 35.4
TA1535 | 0 | 8 ± 2.3 | 12 ± 2.3 | 11 ± 1.5 | 10 ± 0.9 | 15 ± 1.5 | 12 ± 1.8
| 0.1 | 10 ± 0.9 | 11 ± 1.8
| 0.3 | 8 ± 0.9 | 11 ± 1.5
| 1 | 10 ± 0.3 | 10 ± 3.3
| 3 | 11 ± 2.5 | 13 ± 2.1 | 10 ± 1.9 | 9 ± 2.6 | 12 ± 2.7 | 10 ± 1.0
| 10 | 8 ± 1.2 | 6 ± 0.9 | 9 ± 0.3 | 9 ± 1.5 | 10 ± 1.9 | 11 ± 2.2
| 33 | | | 9 ± 1.8 | 10 ± 1.9 | 12 ± 2.0 | 10 ± 2.3
| 100 | | | 7 ± 0.6 | 8 ± 2.2 | 7 ± 0.6 | 15 ± 2.3
| 333 | | | 4 ± 0.9^c^ | 6 ± 0.6 | 9 ± 1.5 | 9 ± 1.5
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 651 ± 20.4 | 443 ± 6.4 | 101 ± 7.3 | 263 ± 18.0 | 100 ± 6.1 | 119 ± 3.4
TA97 | 0 | 98 ± 9.0 | 115 ± 9.8 | 128 ± 6.3 | 151 ± 4.3 | 132 ± 15.3 | 162 ± 4.9
| 0.1 | 112 ± 5.4 | 122 ± 6.7
| 0.3 | 115 ± 4.8 | 133 ± 5.4
| 1 | 119 ± 4.3 | 123 ± 10.7
| 3 | 112 ± 9.4 | 141 ± 10.5 | 124 ± 3.6 | 166 ± 6.0 | 141 ± 8.1 | 154 ± 3.6
| 10 | 118 ± 10.7 | 105 ± 7.8 | 144 ± 7.4 | 172 ± 0.9 | 154 ± 4.4 | 159 ± 3.8
| 33 | | | 157 ± 3.8 | 165 ± 3.5 | 153 ± 8.2 | 165 ± 3.2
| 100 | | | 158 ± 6.6 | 153 ± 3.5 | 152 ± 13.5 | 150 ± 2.8
| 333 | | | 118 ± 9.7 | 149 ± 7.2 | 116 ± 7.4 | 155 ± 6.0
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 341 ± 22.0 | 370 ± 32.7 | 447 ± 13.1 | 439 ± 22.2 | 325 ± 11.0 | 323 ± 20.0
TA98 | 0 | 13 ± 1.2 | 12 ± 2.9 | 20 ± 1.2 | 17 ± 3.6 | 13 ± 1.0 | 17 ± 1.5
| 0.1 | | 13 ± 1.5
| 0.3 | 13 ± 1.8 | 15 ± 3.3
| 1 | 16 ± 4.2 | 11 ± 0.6
| 3 | 13 ± 2.2 | 9 ± 1.2 | 16 ± 1.0 | | 16 ± 0.9
| 10 | 11 ± 1.2 | 11 ± 2.8 | 11 ± 1.0 | 15 ± 2.4 | 12 ± 1.0 | 14 ± 0.6
| 33 | 9 ± 0.3^c^ | | 13 ± 1.3 | 14 ± 1.2 | 13 ± 3.2 | 13 ± 1.5
| 100 | | | 10 ± 2.5 | 13 ± 2.6 | 15 ± 2.3 | 14 ± 0.3
| 333 | | | 8 ± 3.3^c^ | 12 ± 2.1 | 9 ± 0.7^c^ | 11 ± 1.5
| 666 | | | | 13 ± 1.5^c^ | | 7 ± 0.9^c^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 287 ± 25.2 | 298 ± 21.1 | 349 ± 4.7 | 265 ± 17.2 | 226 ± 5.0 | 223 ± 13.1

a Study was performed at SRI International. The detailed protocol is presented by Zeiger et al. (1992). 0 μg/plate was the solvent control.

b Revertants are presented as mean ± standard error from three plates.

c Slight toxicity

d The positive controls in the absence of metabolic activation were sodium azide (TA100 and TA1535), 9-aminoacridine (TA97), and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with all strains was 2-aminoanthracene.

TABLE E2 Induction of Micronuclei in Bone Marrow Polychromatic Erythrocytes of Male F344/N Rats Treated with Dicyclohexylcarbodiimide by Intraperitoneal Injection^a^

Compound | Dose (mg/kg) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Trial 1
Corn oil^d^ | 0 | 5 | 0.4 ± 0.19 | | 52.1 ± 1.10
Dicyclohexylcarbodiimide | 5 | 5 | 0.1 ± 0.10 | 0.910 | 34.5 ± 3.03 | 0.003
| 10 | 4 | 0.5 ± 0.20 | 0.376 | 33.9 ± 2.18 | 0.002
| 15 | 2^e^ | 0.3 ± 0.25 | — | 30.3 ± 7.75 | —
| 20 | 3 | 1.3 ± 0.67 | 0.018 | 33.0 ± 4.31 | 0.050
| | | P=0.006^f^ | | P<0.001^g^
Cyclophosphamide^h^ | 25 | 5 | 15.9 ± 1.64 | <0.001 | 2.3 ± 0.41 | <0.001
Trial 2
Corn oil | 0 | 5 | 0.6 ± 0.37 | | 55.2 ± 4.62
Dicyclohexylcarbodiimide | 10 | 5 | 0.7 ± 0.20 | 0.391 | 51.0 ± 6.07 | 0.599
| 15 | 5 | 1.0 ± 0.45 | 0.159 | 34.2 ± 3.29 | 0.008
| 20 | 5 | 0.7 ± 0.20 | 0.391 | 44.4 ± 7.37 | 0.255
| | | P=0.289 | | P=0.079
Cyclophosphamide | 25 | 5 | 31.3 ± 8.47 | <0.001 | 2.8 ± 0.96 | <0.001

a Study was performed at ILS, Inc. The detailed protocol and these data are presented by Witt et al. (1999). PCE=polychromatic erythrocyte

b Mean ± standard error

c Pairwise comparison with the vehicle control; significant at P≤0.008 (ILS, 1990)

d Vehicle control

e These data were not included in the overall statistical evaluation due to insufficient animals.

f Significance of micronucleated PCEs/1,000 PCEs tested by the one-tailed trend test; significant at P≤0.025 (ILS, 1990)

g ANOVA using individual animal data, significant at P≤0.05

h Positive control

TABLE E3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of B6C3F_1_ Mice Following Dermal Administration of Dicyclohexylcarbodiimide for 13 Weeks^a^

Compound | Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Male
Ethanol^d^ | 0 | 10 | 3.6 ± 0.43 | | 4.8 ± 0.25
Dicyclohexylcarbodiimide | 1.5 | 10 | 3.1 ± 0.48 | 0.730 | 4.3 ± 0.08 | 0.114
| 3 | 10 | 5.3 ± 0.50 | 0.035 | 4.4 ± 0.11 | 0.264
| 6 | 10 | 5.7 ± 0.70 | 0.015 | 4.1 ± 0.14 | 0.048
| 12 | 10 | 5.7 ± 0.68 | 0.015 | 4.3 ± 0.14 | 0.107
| | | P=0.003^e^ | | P=0.071^f^
Female
Ethanol | 0 | 10 | 2.7 ± 0.63 | | 4.3 ± 0.19
Dicyclohexylcarbodiimide | 1.5 | 10 | 3.7 ± 0.58 | 0.105 | 4.9 ± 0.14 | 0.009
| 3 | 10 | 5.1 ± 0.67 | 0.003 | 4.6 ± 0.16 | 0.085
| 6 | 10 | 4.3 ± 0.68 | 0.028 | 4.9 ± 0.22 | 0.015
| 12 | 10 | 4.4 ± 0.50 | 0.022 | 4.5 ± 0.22 | 0.191
| | | P=0.078 | | P=0.096

a Study was performed at Microbiological Associates, Inc. The detailed protocol and these data are presented by Witt et al. (1999). NCE=normochromatic erythrocyte; PCE=polychromatic erythrocyte

b Mean ± standard error

c Pairwise comparison with the vehicle control; significant at P≤0.006 (ILS, 1990)

d Vehicle control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test; significant at P≤0.025 (ILS, 1990)

f ANOVA using individual animal data, significant at P≤0.05