# APPENDIX D SUMMARY OF LESIONS IN FEMALE p53 HAPLOINSUFFICIENT MICE IN THE 27-WEEK DERMAL STUDY OF DICYCLOHEXYLCARBODIIMIDE

TABLE D1 Summary of the Incidence of Neoplasms in Female p53 Haploinsufficient Mice in the 27-Week Dermal Study of Dicyclohexylcarbodiimide^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animais initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Natural deaths | | | | 1 | 1 | 1
Moribund | | | | 2 | | 7
Survivors
Terminal sacrifice | 15 | 15 | 15 | 12 | 14 | 7
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Mesentery | | | | (1)
Lymphoma malignant | | | | 1 (100%)
Hematopoietic System
Lymph node, mandibular | (15) | (15) | (14) | (14) | (14) | (14)
Histiocytic sarcoma | | | | | 1 (7%)
Lymph node, mesenteric | (14) | (15) | (15) | (15) | (14) | (14)
Histiocytic sarcoma | | | | | 1 (7%)
Lymph node, mediastinal | (14) | (15) | (15) | (12) | (13) | (13)
Histiocytic sarcoma | | | | | 1 (8%)
Lymphoma malignant | | | | 1 (8%)
Thymus | (15) | (15) | (15) | (15) | (14) | (13)
Histiocytic sarcoma | | | | | 1 (7%)
Lymphoma malignant | | | | 1 (7%)
Respiratory System
Lung | (15) | (15) | (15) | (15) | (14) | (15)
Lymphoma malignant | | | | 1 (7%)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | | | | 1 (7%)
Lymphoma malignant | | | | 1 (7%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Genital System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System
Urinary System
Neoplasm Summary
Total animais with primary neoplasms^c^ | | | | 1 | 1
Total primary neoplasms | | | | 1 | 1
Total animals with malignant neoplasms | | | | 1 | 1
Total malignant neoplasms | | | | 1 | 1

a Number of animals examined microscopically at site and number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE D2 Summary of the Incidence of Nonneoplastic Lesions in Female p53 Haploinsufficient Mice in the 27-Week Dermal Study of Dicyclohexylcarbodiimide^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animais initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Natural deaths | | | | 1 | 1 | 1
Moribund | | | | 2 | | 7
Survivors
Terminal sacrifice | 15 | 15 | 15 | 12 | 14 | 7
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15) | (14) | (15)
Hematopoietic cell proliferation | | | | | | 1 (7%)
Hematopoietic cell proliferation, focal | | | | | | 1 (7%)
Infiltration cellular, focal, lymphocyte | | 1 (7%) | | 4 (27%) | 1 (7%) | 2 (13%)
Inflammation, chronic active, focal | | | | | | 1 (7%)
Hepatocyte, necrosis, focal | 4 (27%) | 6 (40%) | 5 (33%) | 4 (27%) | 2 (14%) | 1 (7%)
Periportal, vacuolization cytoplasmic, focal | 1 | | | 1 (7%)
Stomach, glandular | (15) | (15) | (15) | (15) | (14) | (14)
Infiltration cellular, focal, lymphocyte | | | | 1 (7%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15) | (14) | (13)
Subcapsular, hyperplasia | | | | | | 1 (8%)
Subcapsular, hyperplasia, focal | 13 (87%) | 13 (87%) | 12 (80%) | 13 (87%) | 14 (100%) | 9 (69%)
Thyroid gland | (13) | (15) | (15) | (14) | (13) | (13)
Ectopic thymus | | 2 (13%) | 3 (20%) | 1 (7%) | 1 (8%)
Inflammation, chronic active, focal | 1 (8%)
General Body System
None
Genital System
Ovary | (15) | (15) | (15) | (15) | (14) | (14)
Atrophy | | | 1 (7%) | | | 1 (7%)
Uterus | (15) | (15) | (15) | (15) | (14) | (14)
Endometrium, hyperplasia, cystic | 14 (93%) | 15 (100%) | 15 (100%) | 13 (87%) | 13 (93%) | 7 (50%)
Hematopoietic System
Bone marrow | (15) | (15) | (15) | (15) | (14) | (15)
Myeloid cell, hyperplasia | | | | 3 (20%) | 1 (7%) | 8 (53%)
Lymph node | | | | (1)
Inguinal, hyperplasia, lymphoid | | | | 1 (100%)
Lymph node, mandibular | (15) | (15) | (14) | (14) | (14) | (14)
Hyperplasia, lymphoid | 1 (7%) | | | 2 (14%) | 3 (21%)
Lymph node, mediastinal | (14) | (15) | (15) | (12) | (13) | (13)
Hyperplasia, lymphoid | | | 1 (7%)
Spleen | (15) | (15) | (15) | (15) | (14) | (14)
Hematopoietic cell proliferation | 15 (100%) | 15 (100%) | 15 (100%) | 15 (100%) | 13 (93%) | 13 (93%)
Pigmentation | | | | | | 1 (7%)
Thymus | (15) | (15) | (15) | (15) | (14) | (13)
Atrophy, diffuse | | | | | | 2 (15%)
Atrophy, focal | | 2 (13%) | 1 (7%)
Integumentary System
Mammary gland | (15) | (15) | (15) | (15) | (14) | (14)
Inflammation, chronic active, focal | | | | | | 1 (7%)
Skin | (15) | (15) | (15) | (15) | (15) | (15)
Control, ulcer, focal | | | | 1 (7%) | | 2 (13%)
Dermis, epidermis, hyperplasia, focal | | | | | | 1 (7%)
Dermis, control, inflammation, chronic active, focal | | | | 3 (20%) | 1 (7%) | 2 (13%)
Dermis, skin, site of application, fibrosis | | | | | | 1 (7%)
Dermis, skin, site of application, inflammation, chronic active, focal | 1 (7%) | | | 13 (87%) | 2 (13%) | 9 (60%)
Epidermis, control, hyperplasia, focal | | | | 2 (13%) | | 1 (7%)
Epidermis, skin, site of application, hyperplasia, diffuse | | | 1 (7%) | 2 (13%)
Epidermis, skin, site of application, hyperplasia, focal | | 1 (7%) | 5 (33%) | 11 (73%) | 1 (7%) | 8 (53%)
Sebaceous gland, control, hyperplasia, focal | | | | 1 (7%) | | 1 (7%)
Sebaceous gland, skin, site of application, hyperplasia, focal | | | | 3 (20%) | | 3 (20%)
Skin, site of application, hyperkeratosis, diffuse | | | | 1 (7%) | 1 (7%)
Skin, site of application, parakeratosis, focal | | | | 1 (7%) | 1 (7%)
Skin, site of application, ulcer, focal | | | | 2 (13%) | 1 (7%) | 8 (53%)
Subcutaneous tissue, control, inflammation, chronic active, focal | | | | 1 (7%) | | 2 (13%)
Subcutaneous tissue, skin, site of application, inflammation, chronic, focal | | | | | 1 (7%)
Subcutaneous tissue, skin, site of application, inflammation, chronic active, focal | | | | 2 (13%) | | 8 (53%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15) | (14) | (15)
Alveolar epithelium, hyperplasia, focal | | | 1 (7%)
Alveolar epithelium, inflammation, chronic active, focal | | 1 (7%)
Alveolus, inflammation, chronic active, focal | 1 (7%) | | | | 1 (7%) | 1 (7%)
Perivascular, infiltration cellular, focal, lymphocyte | 1 (7%) | | | | 2 (14%)
Special Senses System
None
Urinary System
Kidney | (15) | (15) | (15) | (15) | (14) | (14)
Infiltration cellular, focal, lymphocyte | | 1 (7%)
Pelvis, infiltration cellular, focal, lymphocyte | | | | 1 (7%)

a Number of animals examined microscopically at the site and the number of animals with lesion