# APPENDIX C SUMMARY OF LESIONS IN FEMALE Tg.AC HEMIZYGOUS MICE IN THE 20-WEEK DERMAL STUDY OF DICYCLOHEXYLCARBODIIMIDE

TABLE C1 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 20-Week Dermal Study of Dicyclohexylcarbodiimide^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Early deaths
Accidental death | | | | 1
Natural deaths | 1 | 1 | | 1 | | 1
Moribund | 2 | 2 | | 2 | 2
Survivors
Terminal sacrifice | 7 | 7 | 10 | 6 | 8 | 9
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (6) | (6) | (7) | (10) | (10)
Leukemia erythrocytic | 1 (10%) | | 2 (33%) | | 1 (10%)
Pancreas | (10) | (3) | | (4) | (2) | (10)
Leukemia erythrocytic | | | | | 1 (50%)
Stomach, forestomach | (10) | (4) | (2) | (5) | (4) | (10)
Squamous cell papilloma | | 2 (50%) | 2 (100%) | 1 (20%) | 1 (25%)
Tooth | (4) | (5) | (6) | (4) | (5) | (5)
Odontoma | 3 (75%) | 5 (100%) | 6 (100%) | 3 (75%) | 5 (100%) | 5 (100%)
Endocrine System
Thyroid gland | (9) | (4) | | (4) | (2) | (10)
C-cell, adenoma | | 1 (25%)
Hematopoietic System
Lymph node | | (1) | | | (1)
Leukemia erythrocytic | | | | | 1 (100%)
Spleen | (10) | (5) | (5) | (4) | (4) | (10)
Leukemia erythrocytic | | | 2 (40%) | | 1 (25%)
Thymus | (9) | (3) | | (3) | (2) | (10)
Lymphoma malignant | 1 (11%)
Integumentary System
Skin | (10) | (10) | (10) | (10) | (10) | (10)
Squamous cell papilloma | | | 1 (10%) | | | 1 (10%)
Skin, site of application, squamous cell carcinoma | | | | | 1 (10%)
Skin, site of application, squamous cell papilloma | | | | 3 (30%) | 3 (30%) | 3 (30%)
Skin, site of application, squamous cell papilloma, multiple | | | 1 (10%) | | 3 (30%) | 5 (50%)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10) | (10) | (10)
Leukemia erythrocytic | 1 (10%) | | 2 (20%) | | 1 (10%)
Lymphoma malignant | 1 (10%)
Systems Examined with No Neoplasms Observed
Cardiovascular System
General Body System
Genital System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Neoplasm Summary
Total animals with primary neoplasms^c^ | 5 | 6 | 9 | 6 | 8 | 10
Total primary neoplasms | 5 | 8 | 12 | 7 | 14 | 14
Total animals with benign neoplasms | 3 | 6 | 8 | 6 | 8 | 10
Total benign neoplasms | 3 | 8 | 10 | 7 | 12 | 14
Total animals with malignant neoplasms | 2 | | 2 | | 2
Total malignant neoplasms | 2 | | 2 | | 2

a Number of animals examined microscopically at site and number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE C2 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 20-Week Dermal Study of Dicyclohexylcarbodiimide^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Early deaths
Accidental death | | | | 1
Natural deaths | 1 | 1 | | 1 | | 1
Moribund | 2 | 2 | | 2 | 2
Survivors
Terminal sacrifice | 7 | 7 | 10 | 6 | 8 | 9
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Gallbladder | (9) | (3) | | (3) | (2) | (7)
Inflammation | | 1 (33%) | | | | 1 (14%)
Intestine large, rectum | (9) | (3) | | (4) | (2) | (9)
Anus, inflammation | | | | | 1 (50%)
Liver | (10) | (6) | (6) | (7) | (10) | (10)
Fibrosis | | 1 (17%) | | | | 1 (10%)
Hematopoietic cell proliferation | 1 (10%) | 1 (17%) | | | 2 (20%) | 1 (10%)
Inflammation, chronic active, focal | | 3 (50%) | 3 (50%) | 4 (57%) | 6 (60%) | 2 (20%)
Inflammation, focal | 3 (30%) | | | | | 5 (50%)
Necrosis | | 1 (17%) | 1 (17%) | 2 (29%) | 1 (10%)
Necrosis, focal | 1 (10%) | | | | | 1 (10%)
Stomach, forestomach | (10) | (4) | (2) | (5) | (4) | (10)
Inflammation | | 1 (25%)
Stomach, glandular | (10) | (3) | | (4) | (2) | (10)
Inflammation | 1 (10%) | | | | | 1 (10%)
Serosa, fibrosis | | | | | | 1 (10%)
Tooth | (4) | (5) | (6) | (4) | (5) | (5)
Inflammation, chronic active | | | | | | 1 (20%)
Cardiovascular System
Heart | (10) | (3) | | (4) | (2) | (10)
Inflammation, acute | | | | | | 1 (10%)
Mineralization, focal | | | | | | 1 (10%)
Endocrine System
Pituitary gland | (10) | (2) | | (3) | (1) | (8)
Pars distalis, necrosis, focal | | | | | 1 (100%)
General Body System
None
Genital System
Clitoral gland | (8) | (1) | | (4) | (1) | (9)
Inflammation | | | | | | 1 (11%)
Uterus | (10) | (3) | | (4) | (2) | (10)
Cyst | 1 (10%) | | | | | 1 (10%)
Bilateral, cyst | | | | | | 1 (10%)
Hematopoietic System
Bone marrow | (10) | (3) | | (4) | (2) | (10)
Hyperplasia | 3 (30%) | | | 2 (50%) | 1 (50%) | 2 (20%)
Myeloid cell, hyperplasia | | 1 (33%)
Lymph node | | (1) | | | (1)
Bronchial, infiltration cellular, plasma cell | | 1 (100%)
Lymph node, mandibular | (10) | (3) | (1) | (4) | (3) | (10)
Hematopoietic cell proliferation | | 1 (33%)
Hemorrhage | | | | 1 (25%)
Infiltration cellular, plasma cell | | | 1 (100%) | | | 1 (10%)
Infiltration cellular, histiocyte | 2 (20%) | | | | | 1 (10%)
Lymph node, mesenteric | (9) | (3) | | (4) | (2) | (9)
Hematopoietic cell proliferation | | 1 (33%)
Infiltration cellular, histiocyte | 1 (11%)
Necrosis, focal | 1 (11%) | | | 1 (25%)
Spleen | (10) | (5) | (5) | (4) | (4) | (10)
Fibrosis | | | | | | 1 (10%)
Hematopoietic cell proliferation | 8 (80%) | 4 (80%) | 4 (80%) | 3 (75%) | 3 (75%) | 9 (90%)
Lymphoid follicle, depletion cellular | | | | | | 1 (10%)
Thymus | (9) | (3) | | (3) | (2) | (10)
Atrophy | 1 (11%) | 2 (67%) | | 1 (33%) | 2 (100%) | 1 (10%)
Hemorrhage | | | | | | 1 (10%)
Integumentary System
Skin | (10) | (10) | (10) | (10) | (10) | (10)
Hemorrhage | | | | 1 (10%)
Hyperplasia | | | | | | 1 (10%)
Inflammation, chronic active | | | 1 (10%)
Dermis, inflammation | | | | | 1 (10%)
Dermis, inflammation, chronic active | | | | 1 (10%)
Dermis, skin, site of application, inflammation, chronic active | | | 3 (30%) | 5 (50%) | 8 (80%)
Epidermis, skin, site of application, hyperplasia | | | | 6 (60%) | 7 (70%) | 1 (10%)
Musculoskeletal System
Bone | (10) | (3) | | (4) | (2) | (10)
Synovial tissue, inflammation | 1 (10%)
Nervous System
Brain | (10) | (3) | | (4) | (2) | (10)
Hemorrhage, acute | | | | 1 (25%)
Respiratory System
Larynx | | | | | | (1)
Inflammation | | | | | | 1 (100%)
Lung | (10) | (3) | | (4) | (2) | (10)
Hemorrhage, acute | | | | 1 (25%)
Inflammation, chronic active | | | | | | 4 (40%)
Nose | (10) | (3) | | (4) | (5) | (10)
Inflammation | | | | | 3 (60%) | 1 (10%)
Respiratory epithelium, inflammation | | | | | | 1 (10%)
Special Senses System
None
Urinary System
Kidney | (10) | (3) | | (4) | (2) | (10)
Inflammation, chronic active | | 1 (33%)
Bilateral, inflammation | | | | | | 1 (10%)
Cortex, cyst | 1 (10%)

a Number of animals examined microscopically at the site and the number of animals with lesion