# APPENDIX B SUMMARY OF LESIONS IN B6C3F_1_ MICE IN THE 13-WEEK DERMAL STUDY OF DICYCLOHEXYLCARBODIIMIDE

TABLE B1 Summary of the Incidence of Nonneoplastic Lesions in Male B6C3F_1_ Mice in the 13-Week Dermal Study of Dicyclohexylcarbodiimide^a^

| Vehicle Control | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg | 24 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Early deaths
Accidental deaths | 1 | 1 | 2
Moribund | | | | | | 9
Natural death | | | | | | 1
Survivors
Terminal sacrifice | 9 | 9 | 8 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | | | | (10) | (10)
Inflammation, focal | | | | | 1 (10%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (10) | | | | (10) | (9)
Bilateral, capsule, hyperplasia | 1 (10%)
Capsule, hyperplasia | 1 (10%) | | | | 3 (30%)
General Body System
None
Genital System
Preputial gland | (9) | (10) | (10) | (10) | (10) | (10)
Atrophy | | | | 1 (10%)
Bilateral, atrophy | | | | | | 4 (40%)
Hematopoietic System
Spleen | (10) | (10) | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | | 5 (50%) | 2 (20%) | 7 (70%) | 6 (60%) | 6 (60%)
Thymus | (9) | (10) | (9) | (9) | (10) | (8)
Atrophy | | | | | | 8 (100%)
Thymocyte, necrosis | | | | | 1 (10%)
Integumentary System
Skin | (10) | (10) | (10) | (10) | (10) | (10)
Hyperplasia | | 1 (10%)
Control, inflammation | | | | | 1 (10%)
Control, inflammation, chronic active | | 1 (10%) | 1 (10%) | 1 (10%) | 3 (30%)
Epidermis, control, hyperplasia | | | 1 (10%)
Epidermis, control, necrosis | | | | | 2 (20%)
Epidermis, control, necrosis, diffuse | | | | | 1 (10%)
Epidermis, skin, site of application, hyperplasia | | 7 (70%) | 10 (100%) | 10 (100%) | 10 (100%)
Epidermis, skin, site of application, necrosis | 1 (10%) | | | | 2 (20%) | 10 (100%)
Epidermis, skin, site of application, necrosis, focal | | | | 2 (20%)
Skin, site of application, inflammation, chronic active | | 4 (40%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Musculoskeletal System
None
Nervous System
Brain | (10) | (10) | (10) | (10) | (10) | (10)
Pons, hemorrhage | | | | | | 2 (20%)
Respiratory System
None
Special Senses System
None
Urinary System
None

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE B2 Summary of the Incidence of Neoplasms and Nonneoplastic Lesions in Female B63CF_1_ Mice in the 13-Week Dermal Study of Dicyclohexylcarbodiimide^a^

| Vehicle Control | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg | 24 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Early deaths
Accidental death | | 1
Moribund | | | | | | 10
Survivors
Terminal sacrifice | 10 | 9 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | | | | (10) | (10)
Inflammation, focal | 1 (10%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (10) | | | | (10) | (10)
Bilateral, capsule, hyperplasia | 5 (50%) | | | | 7 (70%)
Capsule, hyperplasia | 2 (20%) | | | | 2 (20%)
Pituitary gland | (9) | | | | (9) | (8)
Pars distalis, cyst | | | | | | 1 (13%)
General Body System
None
Genital System
Clitoral gland | (8) | (7) | (5) | (9) | (7) | (10)
Bilateral, atrophy | | | | | | 1 (10%)
Hematopoietic System
Lymph node | | | | | (1)
Inguinal, hyperplasia | | | | | 1 (100%)
Spleen | (10) | (10) | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 2 (20%) | 2 (20%) | 7 (70%) | 9 (90%) | 5 (50%) | 3 (30%)
Thymus | (10) | (10) | (10) | (9) | (10) | (8)
Atrophy | | | | | | 8 (100%)
Thymocyte, necrosis | | | | | | 1 (13%)
Integumentary System
Skin | (10) | (10) | (10) | (10) | (10) | (10)
Control, inflammation | 1 (10%) | | | | | 1 (10%)
Control, inflammation, chronic active | 1 (10%) | | 3 (30%) | 5 (50%) | 5 (50%)
Epidermis, control, hyperplasia | | | | | 3 (30%)
Epidermis, skin, site of application, hyperplasia | | 5 (50%) | 9 (90%) | 10 (100%) | 10 (100%) | 3 (30%)
Epidermis, skin, site of application, necrosis | | | | 2 (20%) | 3 (30%) | 10 (100%)
Epidermis, skin, site of application, necrosis, focal | | | | 1 (10%)
Skin, site of application, inflammation, chronic active | | 1 (10%) | 9 (90%) | 10 (100%) | 10 (100%) | 10 (100%)
Musculoskeletal System
None
Nervous System
Brain | (10) | (10) | (10) | (10) | (10) | (10)
Lipoma | | | | 1 (10%)
Pons, hemorrhage | | | | | | 6 (60%)
Respiratory System
None
Special Senses System
None
Urinary System
None

a Number of animals examined microscopically at the site and the number of animals with lesion