# APPENDIX A SUMMARY OF LESIONS IN F344/N RATS IN THE 13-WEEK DERMAL STUDY OF DICYCLOHEXYLCARBODIIMIDE

TABLE A1 Summary of the Incidence of Nonneoplastic Lesions in Male F344/N Rats in the 13-Week Dermal Study of Dicyclohexylcarbodiimide^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Early deaths
Moribund | | | | | | 8
Natural deaths | | | | | | 2
Survivors
Terminal sacrifice | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | | | | (10) | (10)
Hepatodiaphragmatic nodule | 1 (10%)
Inflammation, chronic active | | | | | | 1 (10%)
Stomach, forestomach | (10) | | | | (10) | (10)
Hyperplasia, atypical, focal | | | | | 1 (10%)
Inflammation, acute, focal | | | | | 1 (10%)
Cardiovascular System
Heart | (10) | | | | (10) | (10)
Cardiomyopathy | 1 (10%) | | | | 3 (30%) | 2 (20%)
Endocrine System
None
General Body System
None
Genital System
Preputial gland | (10) | | | | (10) | (10)
Inflammation, chronic, focal | 1 (10%) | | | | 1 (10%)
Inflammation, chronic active, focal | 1 (10%)
Hematopoietic System
Bone marrow | (10) | (10) | (10) | (10) | (10) | (10)
Hyperplasia, diffuse | | | | | | 10 (100%)
Spleen | (10) | (10) | (10) | (10) | (10) | (10)
Depletion cellular, diffuse | | | | | | 1 (10%)
Hematopoietic cell proliferation, focal | | 1 (10%) | 1 (10%) | 1 (10%) | 2 (20%) | 1 (10%)
Thymus | (10) | | | | (10) | (10)
Atrophy | | | | | | 1 (10%)
Necrosis, diffuse | | | | | | 2 (20%)
Integumentary System
Skin | (10) | (10) | (10) | (10) | (10) | (10)
Control, inflammation, chronic active | | | | | 3 (30%) | 2 (20%)
Epidermis, control, hyperplasia | | | | | 5 (50%) | 1 (10%)
Epidermis, control, necrosis | | | | | 1 (10%) | 1 (10%)
Epidermis, skin, site of application, hyperplasia | | 1 (10%) | 3 (30%) | 9 (90%) | 10 (100%) | 10 (100%)
Epidermis, skin, site of application, hyperplasia, focal | | 1 (10%)
Epidermis, skin, site of application, necrosis | | | | | | 6 (60%)
Sebaceous gland, skin, site of application, hyperplasia | | 1 (10%) | 1 (10%) | 4 (40%) | 7 (70%) | 6 (60%)
Skin, site of application, inflammation, acute, diffuse | | | | | | 1 (10%)
Skin, site of application, inflammation, chronic active | | 1 (10%) | | 1 (10%) | 7 (70%) | 9 (90%)
Skin, site of application, inflammation, granulomatous | | | | | | 1 (10%)
Musculoskeletal System
None
Nervous System
Brain | (10) | (10) | (10) | (10) | (10) | (10)
Hemorrhage | | | | | | 1 (10%)
Respiratory System
Lung | (10) | (10) | (10) | (8) | (10) | (10)
Congestion, diffuse | | | | | | 2 (20%)
Inflammation, chronic active, focal | 8 (80%) | 8 (80%) | 7 (70%) | 7 (88%) | 9 (90%) | 3 (30%)
Special Senses System
None
Urinary System
Kidney | (10) | | | | (10) | (10)
Nephropathy | 6 (60%) | | | | 5 (50%) | 2 (20%)
Renal tubule, degeneration, focal | 1 (10%)
Urinary bladder | (10) | | | | (10) | (10)
Hemorrhage | | | | | | 1 (10%)

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A2 Summary of the Incidence of Nonneoplastic Lesions in Female F344/N Rats in the 13-Week Dermal Study of Dicyclohexylcarbodiimide^a^

| Vehicle Control | 0.75 mg/kg | 1.5 mg/kg | 3 mg/kg | 6 mg/kg | 12 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Early deaths
Accidental deaths | 2
Moribund | | | | | | 10
Survivors
Terminal sacrifice | 8 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | | | (1) | (10) | (10)
Hepatodiaphragmatic nodule | | | | 1 (100%)
Cardiovascular System
Heart | (10) | | | | (10) | (10)
Cardiomyopathy | 1 (10%) | | | | 1 (10%) | 4 (40%)
Endocrine System
Pituitary gland | (10) | | | | (10) | (9)
Pars distalis, cyst | | | | | | 1 (11%)
General Body System
None
Genital System
Clitoral gland | (10) | | | | (9) | (10)
Inflammation, chronic active, focal | | | | | 1 (11%)
Uterus | (10) | | (1) | (1) | (10) | (10)
Hydrometra | | | 1 (100%) | 1 (100%) | 2 (20%)
Bilateral, hydrometra | 1 (10%)
Hematopoietic System
Bone marrow | (10) | (10) | (10) | (10) | (10) | (10)
Hyperplasia, diffuse | | | | | 1 (10%) | 9 (90%)
Hyperplasia, focal, histiocytic | 4 (40%) | | 4 (40%) | 2 (20%) | 1 (10%)
Lymph node | | | | | (1)
Hyperplasia, diffuse, lymphoid | | | | | 1 (100%)
Integumentary System
Skin | (10) | (10) | (10) | (10) | (10) | (10)
Control, inflammation, chronic active | | | | 1 (10%) | 1 (10%) | 2 (20%)
Dermis, skin, site of application, edema, focal | | | | | | 1 (10%)
Dermis, skin, site of application, inflammation, chronic active | | | | | | 1 (10%)
Epidermis, control, hyperplasia | | 1 (10%) | 1 (10%) | | 1 (10%) | 1 (10%)
Epidermis, control, necrosis | | | | | | 1 (10%)
Epidermis, skin, site of application, hyperplasia | | 3 (30%) | 7 (70%) | 7 (70%) | 10 (100%) | 10 (100%)
Epidermis, skin, site of application, necrosis | | | | | 1 (10%) | 3 (30%)
Epidermis, skin, site of application, necrosis, focal | | | | | | 1 (10%)
Sebaceous gland, skin, site of application, hyperplasia | | 1 (10%) | | | 5 (50%) | 7 (70%)
Skin, site of application, inflammation, acute | | | | | 1 (10%)
Skin, site of application, inflammation, chronic active | | | 4 (40%) | 4 (40%) | 9 (90%) | 9 (90%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (10) | (9) | (10) | (9) | (10) | (10)
Inflammation, chronic active, focal | 8 (80%) | 9 (100%) | 6 (60%) | 7 (78%) | 7 (70%) | 2 (20%)
Special Senses System
None
Urinary System
Kidney | (10) | | | | (10) | (10)
Nephropathy | 2 (20%) | | | | 1 (10%) | 4 (40%)

a Number of animals examined microscopically at the site and the number of animals with lesion