# REFERENCES

Ackermann, J., Frutschi, M., Kaloulis, K., McKee, T., Trumpp, A., and Beermann, F. (2005). Metastasizing melanoma formation caused by expression of activated N-Ras^Q61K^ on an INK4a-deficient background. Cancer Res. 65, 4005–4011.15899789
Agency for Toxic Substances and Disease Registry (ATSDR) (1997). Toxicological Profile for Benzene. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
Agency for Toxic Substances and Disease Registry (ATSDR) (2005). Toxicologic Profile for Benzene. <http://www.atsdr.cdc.gov/toxprofiles/tp3.html>
The Aldrich Library of Infrared Spectra (1981). 3rd ed. (C.J. Pouchert, Ed.), spectrum 561A. Aldrich Chemical Company Inc., Milwaukee, WI.
The Aldrich Library of NMR Spectra (1983). 2nd ed. (C.J. Pouchert, Ed.), Vol. 1, spectrum 733A. Aldrich Chemical Company Inc., Milwaukee, WI.
The Aldrich Library of FT-IR Spectra (1985). 1st ed. (C.J. Pouchert, Ed.), p. 931A, spectrum 1. Aldrich Chemical Company Inc., Milwaukee, WI.
Armitage, P. (1971). Statistical Methods in Medical Research, pp. 362–365. John Wiley and Sons, New York.
Bardeesy, N., Bastian, B.C., Hezel, A., Pinkel, D., DePinho, R.A., and Chin, L. (2001). Dual inactivation of RB and p53 pathways in RAS-induced melanomas. Mol. Cell Biol. 21, 2144–2153.11238948
Bauer, A.K., Faiola, B., Abernethy, D.J., Marchan, R., Pluta, L.J., Wong, V.A., Gonzalez, F.J., Butterworth, B.E., Borghoff, S.J., Everitt, J.I., and Recio, L. (2003). Male mice deficient in microsomal epoxide hydrolase are not susceptible to benzene-induced toxicity. Toxicol. Sci. 72, 201–209.12655032
Boley, S.E., Wong, V.A., French, J.E., and Recio, L. (2002). p53 Heterozygosity alters the mRNA expression of p53 target genes in the bone marrow in response to inhaled benzene. Toxicol. Sci. 66, 209–215.11896287
Boorman, G.A., Montgomery, C.A., Jr., Eustis, S.L., Wolfe, M.J., McConnell, E.E., and Hardisty, J.F. (1985). Quality assurance in pathology for rodent carcinogenicity studies. In Handbook of Carcinogen Testing (H.A. Milman and E.K. Weisburger, Eds.), pp. 345–357. Noyes Publications, Park Ridge, NJ.
Boorman, G.A., Hickman, R.L., Davis, G.W., Rhodes, L.S., White, N.W., Griffin, T.A., Mayo, J., and Hamm, T.E., Jr. (1986). Serological titers to murine viruses in 90 day and 2 year studies. In Complications of Viral and Mycoplasmal Infections in Rodents to Toxicology Research and Testing (T.E. Hamm, Jr., Ed.), pp. 11–23. Hemisphere Publishing Corporation, Washington, DC.
Cavalieri, E.L., and Rogan, E.G. (2004). A unifying mechanism in the initiation of cancer and other diseases by catechol quinones. Ann. N. Y. Acad. Sci. 1028, 247–257.15650250
Chen, H., Rupa, D.S., Tomar, R., and Eastmond, D.A. (1994). Chromosomal loss and breakage in mouse bone marrow and spleen cells exposed to benzene in vivo. Cancer Res. 4, 3533–3539.
Chen, K.M., El-Bayoumy, K., Cunningham, J., Aliaga, C., Li, H., and Melikian, A.A. (2004). Detection of nitrated benzene metabolites in bone marrow of B6C3F1 mice treated with benzene. Chem. Res. Toxicol. 17, 370–377.15025507
Chin, L., Pomerantz, J., Polsky, D., Jacobson, M., Cohen, C., Cordon-Cardo, C., Horner, J.W., II, and DePinho, R.A. (1997). Cooperative effects of INK4a and ras in melanoma susceptibility in vivo. Genes Dev. 11, 2822–2834.9353252
Choy, W.N., MacGregor, J.T., Shelby, M.D., and Maronpot, R.R. (1985). Induction of micronuclei by benzene in B6C3F1 mice: Retrospective analysis of peripheral blood smears from the NTP carcinogenesis bioassay. Mutat. Res. 143, 55–59.4000143
Ciranni, R., Barale, R., and Adler, I.D. (1991). Dose-related clastogenic effects induced by benzene in bone marrow cells and in differentiating spermatogonia of Swiss CD1 mice. Mutagenesis 6, 417–421.1795648
Code of Federal Regulations (CFR) 21, Part 58.
Cole, C.E., Tran, H.T., and Schlosser, P.M. (2001). Physiologically based pharmacokinetic modeling of benzene metabolism in mice through extrapolation from in vitro to in vivo. J. Toxicol. Environ. Health A 62, 439–465.11289318
Cornish, H., and Ryan, R. (1965). Metabolism of benzene in nonfasted, fasted, and aryl-hydroxylase inhibited rats. Toxicol. Appl. Pharmacol. 7, 767–771.5895051
Corti, M., and Snyder, C.A. (1998). Gender- and age-specific cytotoxic susceptibility to benzene metabolites in vitro. Toxicol. Sci. 41, 42–48.9520340
Cox, D.R. (1972). Regression models and life-tables. J. R. Stat. Soc. B34, 187–220.
Cronkite, E.P., Drew, R.T., Inoue, T., Hirabayashi, Y., and Bullis, J.E. (1989). Hematotoxicity and carcinogenicity of inhaled benzene. Environ. Health Perspect. 82, 97–108.2792054
Dean, B.J. (1978). Genetic toxicology of benzene, toluene, xylenes and phenols. Mutat. Res. 47, 75–97.415231
Dixon, W.J., and Massey, F.J., Jr. (1957). Introduction to Statistical Analysis, 2nd ed., pp. 276–278, 412. McGraw-Hill Book Company, Inc., New York.
Dunn, O.J. (1964). Multiple comparisons using rank sums. Technometrics 6, 241–252.
Dunnett, C.W. (1955). A multiple comparison procedure for comparing several treatments with a control. J. Am. Stat. Assoc. 50, 1096–1121.
Eastmond, D.A. (2000). Benzene-induced genotoxicity: A different perspective. J. Toxicol. Environ Health A. 61, 353–356.11086939
Faiola, B., Fuller, E.S., Wong, V.A., Pluta, L., Abernethy, D.J., Rose, J., and Recio, L. (2004). Exposure of hematopoietic stem cells to benzene or 1,4-benzoquinone induces gender-specific gene expression. Stem Cells 22, 750–758.15342939
Farris, G.M., Everitt, J.I., Irons, R.D., and Popp, J.A. (1993). Carcinogenicity of inhaled benzene in CBA mice. Fundam. Appl. Toxicol. 20, 503–507.8314465
Foureman, P., Mason, J.M., Valencia, R., and Zimmering, S. (1994). Chemical mutagenesis testing in Drosophila. X. Results of 70 coded chemicals tested for the National Toxicology Program. Environ. Mol. Mutagen. 23, 208–227.8162896
French, J., Storer, R.D., and Donehower, L.A. (2001). The nature of the heterozygous Trp53 knockout model for identification of mutagenic carcinogens. Toxicol. Pathol. 29 (Suppl.), 24–29.11695559
Gaskell, M., McLuckie, K.I., and Farmer, P.B. (2005). Comparison of the repair of DNA damage induced by the benzene metabolites hydroquinone and p-benzoquinone: A role for hydroquinone in benzene genotoxicity. Carcinogenesis 26, 673–680.15618234
Gart, J.J., Chu, K.C., and Tarone, R.E. (1979). Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. JNCI 62, 957–974.285297
Goldstein, B.D., Snyder, C.A., Laskin, S., Bromberg, I., Albert, R.E., and Nelson, N. (1982). Myelogenous leukemia in rodents inhaling benzene. Toxicol. Lett. 13, 169–173.6959383
Gulati, D.K., Witt, K., Anderson, B., Zieger, E., and Shelley, M.D. (1989). Chromosome aberration and sister chromatid exchange tests in Chinese hamster ovary cells in vitro III: Results with 27 chemicals. Environ. Mol. Mutagen. 13, 133–193.2917552
Hayes, R.B., Songnian, Y., Dosemeci, M., and Linet, M. (2001). Benzene and lymphohematopoietic malignancies in humans. Am. J. Ind. Med. 40, 714–716.11757049
Hollander, M., and Wolfe, D.A. (1973). Nonparametric Statistical Methods, pp. 120–123. John Wiley and Sons, New York.
Huff, J.E., Haseman, J.K., DeMarini, D.M., Eustis, S., Maronpot, R.R., Peters, A.C., Persing, R.L., Chrisp, C.E., and Jacobs, A.C. (1989). Multiple-site carcinogenicity of benzene in Fischer 344 rats and B6C3F1 mice. Environ. Health Perspect. 82, 125–163.2676495
Humble, M.C., Trempus, C.S., Spalding, J.W., Cannon, R.E., and Tennant, R.W. (2005). Biological, cellular, and molecular characteristics of an inducible transgenic skin tumor model: A review. Oncogene 24, 8217–8228.16355251
Integrated Laboratory Systems (ILS) (1990). Micronucleus Data Management and Statistical Analysis Software, Version 1.4. ILS, Inc., P.O. Box 13501, Research Triangle Park, NC 27707.
International Agency for Research on Cancer (IARC) (1982). Benzene. In IARC Monographs on the Evaluation of the Carcinogenic Risk of Chemicals to Humans. Some Industrial Chemicals and Dyestuffs, Vol. 29, pp. 95–148. IARC, Lyon, France
International Agency for Research on Cancer (IARC) (1987). Genetic and Related Effects. In IARC Monographs on the Evaluation of the Carcinogenic Risks to Humans. Overall Evaluations of Carcinogenicity: An Updating of IARC Monographs Volumes 1 to 42, (Suppl. 7). IARC, Lyon, France.
Irons, R.D. (1985). Quinones as toxic metabolites of benzene. J. Toxicol. Environ. Health 16, 673–678.4093989
Jonckheere, A.R. (1954). A distribution-free k-sample test against ordered alternatives. Biometrika 41, 133–145.
Kaplan, E.L., and Meier, P. (1958). Nonparametric estimation from incomplete observations. J. Am. Stat. Assoc. 53, 457–481.
Kašuba, V., Rozgaj, R., and Šentija, K. (2000). Cytogenetic changes in subjects occupationally exposed to benzene. Chemosphere 40, 307–310.10665421
Kenyon, E.M., Kraichely, R.E., Hudson, K.T., and Medinsky, M.A. (1996). Differences in rates of benzene metabolism correlate with observed genotoxicity. Toxicol. Appl. Pharmacol. 136, 49–56.8560479
Kimura, E., Ebert, D., and Dodge, P. (1971). Acute toxicity and limits of solvent residue for sixteen organic solvents. Toxicol. Appl. Pharmacol. 19, 699–704.5132037
Lowe, S.W., and Sherr, C.J. (2003). Tumor suppression by INK4a/Arf: Progress and puzzles. Curr. Opin. Genet. Dev. 13, 77–83.12573439
McConnell, E.E., Solleveld, H.A., Swenberg, J.A., and Boorman, G.A. (1986). Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. JNCI 76, 283–289.3456066
MacGregor, J.T., Wehr, C.M., Henika, P.R., and Shelby, M.D. (1990). The in vivo erythrocyte micronucleus test: Measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam. Appl. Toxicol. 14, 513–522.2111256
McMahon, T.F., and Birnbaum, L.S. (1991). Age-related changes in disposition and metabolism of benzene in male C57BL/6N mice. Drug Metab. Dispos. 19, 1052–1057.1687010
Maltoni, C., Conti, B., and Cotti, G. (1983). Benzene: A multipotential carcinogen. Results of long-term bioassays performed at the Bologna Institute of Oncology. Am. J. Ind. Med. 4, 589–630.6353911
Maltoni, C., Conti, B., Perino, G., and Di Maio, V. (1988). Further evidence of benzene carcinogenicity. Results on Wistar rats and Swiss mice treated by ingestion. Ann. N.Y. Acad. Sci. 534, 412–426.3389671
Marcon, F., Zijno, A., Crebelli, R., Carere, A., Veidebaum, T., Peltonen, K., Parks, R., Schuler, M., and Eastmond, D. (1999). Chromosome damage and aneuploidy detected by interphase multicolour FISH in benzene-exposed shale oil workers. Mutat. Res. 445, 155–166.10575426
Maronpot, R.R., and Boorman, G.A. (1982). Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol. Pathol. 10, 71–80.28094716
The Merck Index (1996). 12th ed. (S. Budavari, Ed.), p. 178. Merck & Company, Whitehouse Station, NJ.
Morrison, S.J., and Weissman, I.L. (1994). The long-term repopulating subset of hematopoietic stem cells is deterministic and isolatable by phenotype. Immunity 1, 661–673.7541305
Myhr, B., Bowers, L., and Caspary, W.J. (1985). Assays for the induction of gene mutations at the thymidine kinase locus in L5178Y mouse lymphoma cells in culture. In Progress in Mutation Research: Evaluation of Short-term Tests for Carcinogens; Report of the International Programme on Chemical Safety’s Collaborative Study on In vitro Assays (J. Ashby, F.J. de Serres, M. Draper, M. Ishidate, Jr., B.H. Margolin, B.E. Matter, and M.D. Shelby, Eds.), Vol. 5, pp. 555–568. Elsevier Science Publishers, Amsterdam.
National Center for Biotechnology Information (NCBI) (2005). Unigene, http://www.ncbi.nlm.nih.gov/entrez/query.fcgi?CMD=search&DB=unigene.
National Toxicology Program (NTP) (1986). Toxicology and Carcinogenesis Studies of Benzene (CAS No. 71-43-2) in F344/N Rats and B6C3F_1_ Mice (Gavage Studies). Technical Report Series No. 289. NIH Publication No. 86-2545. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (1990). Toxicology and Carcinogenesis Studies of Glycidol (CAS No. 556-52-5) in F344/N Rats and B6C3F_1_ Mice. Technical Report Series No. 374. NIH Publication No. 90-2829. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (1996). Toxicology and Carcinogenesis Studies of Phenolphthalein (CAS No. 77-09-8) in F344/N Rats and B6C3F_1_ Mice (Feed Studies). Technical Report Series No. 465. NIH Publication No. 97-3390. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (2004). Report on Carcinogens, 11th ed., pp. 130–131. U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program, Research Triangle Park, NC.
National Toxicology Program (NTP) (2005). Toxicology Studies of Aspartame (CAS No. 22839-47-0) in Genetically Modified (FVB Tg.AC Hemizygous) and B6.129-Cdkn2^atm1Rdp^ (N2) Deficient Mice and Carcinogenicity Studies of Aspartame in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient Mice (Feed Studies). GMM Report Series No. 1. NIH Publication No. 06-4459. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2008a). Toxicology and Carcinogenesis Study of Glycidol (CAS No. 556-52-5) in Genetically Modified Haploinsufficient p16^Ink4a^/p19^Arf^ Mice (Gavage Study). GMM Report Series No. 13. NIH Publication No. 08-5962. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC (in press).
National Toxicology Program (NTP) (2008b). Toxicology and Carcinogenesis Study of Phenolphthalein (CAS No. 77-09-8) in Genetically Modified Haploinsufficient p16^Ink4a^/p19^Arf^ Mice (Gavage Study). GMM Report Series No. 12. NIH Publication No. 08-5961. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC (in press).
Powley, M.W., and Carlson, G.P. (1999). Species comparison of hepatic and pulmonary metabolism of benzene. Toxicology 139, 207–217.10647921
Quelle, D.E., Zindy, F., Ashmun, R.A., and Sherr, C.J. (1995). Alternative reading frames of the INK4a tumor suppressor gene encode two unrelated proteins capable of inducing cell cycle arrest. Cell 83, 993–1000.8521522
Ranaldi, R., Bassani, B., Villani, P., Lombardi, C.C., Tanzarella, C., and Pacchierotti, F. (1998). Measurement and characterization of micronuclei in cultured primary lung cells of mice following inhalation exposure to benzene. Mutagenesis 13, 453–460.9800190
Rao, G.N., Haseman, J.K., and Edmondson, J. (1989a). Influence of viral infections on body weight, survival, and tumor prevalence in Fischer 344/NCr rats on two-year studies. Lab. Anim. Sci. 39, 389–393.2554057
Rao, G.N., Piegorsch, W.W., Crawford, D.D., Edmondson, J., and Haseman, J.K. (1989b). Influence of viral infections on body weight, survival, and tumor prevalence of B6C3F1 (C57BL/6N × C3H/HeN) mice in carcinogenicity studies. Fundam. Appl. Toxicol. 13, 156–164.2767355
Recio, J.A., Noonan, F.P., Takayama, H., Anver, M.R., Duray, P., Rush, W.L., Lindner, G., De Fabo, E.C., DePinho, R.A., and Merlino, G. (2002). Ink4a/arf deficiency promotes ultraviolet radiation-induce melanoma-genesis. Cancer Res. 62, 6724–6730.12438273
Recio, L., Pluta, L., Abernethy, D., James, A., Boley, S., Everitt, J., Cole, C., Schlosser, P., Walker, D., and French, J.E. (2006). Differential induction of thymic lymphomas in p53+/+ and p53+/− mice exposed to inhaled benzene (in press).
Rinsky, R.A., Young, R.J., and Smith, A.B. (1981). Leukemia in benzene workers. Am. J. Ind. Med. 2, 217–245.7345926
Rinsky, R.A., Smith, A.B., Hornung, R., Filloon, T.G., Young, R.J., Okun, A.H., and Landrigan, P.J. (1987). Benzene and leukemia. An epidemiologic risk assessment. N. Engl. J. Med. 316, 1044–1050.3561457
Rithidech, K., Au, W.W., Ramanujam, V.M., Whorton, E.B., Jr., and Legator, M.S. (1987). Induction of chromosome aberrations in lymphocytes of mice after subchronic exposure to benzene. Mutat. Res. 188, 135–140.3587261
Rivedal, E., and Witz, G. (2005). Metabolites of benzene are potent inhibitors of gap-junction intercellular communication. Arch. Toxicol. 79, 303–311.15690152
Robles, H. (1998). Benzene. In Encyclopedia of Toxicology (P. Wexler, Ed.), Vol. 1, pp. 133–134. Academic Press, New York.
Ross, D. (2000). The role of metabolism and specific metabolites in benzene-induced toxicity: Evidence and issues. J. Toxicol. Environ. Health A 61, 357–372.11086940
Sabourin, P.J., Bechtold, W.E., Griffith, W.C., Birnbaum, L.S., Lucier, G., and Henderson, R.F. (1989). Effect of exposure concentration, exposure rate, and route of administration on metabolism of benzene by F344 rats and B6C3F_1_ mice. Toxicol. Appl. Pharmacol. 99, 421–444.2749731
Sanders, J.M., Burka, L.T., Chanas, B., and Matthews, H.B. (2001). Comparative xenobiotic metabolism between Tg.AC and p53+/− genetically altered mice and their respective wild types. Toxicol. Sci. 61, 54–61.11294974
Serrano, M., Hannon, G.J., and Beach, D. (1993). A new regularity motif in cell-cycle control causing specific inhibition of cyclin D/CDK4. Nature 366, 704–707.8259215
Serrano, M., Lee, H.-W., Chin, L., Cordon-Cardo, C., Beach, D., and DePinho, R.A. (1996). Role of the INK4a locus in tumor suppression and cell mortality. Cell 85, 27–37.8620534
Sharpless, N.E. (2005). INK4a/ARF: A multifunctional tumor suppressor locus. Mutat. Res. 576, 22–38.15878778
Sharpless, N.E., and DePinho, R.A. (1999). The INK4A/Arf locus and its two gene products. Curr. Opin. Genet. Dev. 9, 22–30.10072356
Shelby, MD. (1988). The genetic toxicity of human carcinogens and its implications. Mutat. Res. 204, 3–15.3277048
Sherr, C.J., and McCormick, F. (2002). The RB and p53 pathways in cancer. Cancer Cell 2, 103–112.12204530
Sherr, C.J., and Weber, J.D. (2000). The Arf/p53 pathway. Curr. Opin. Genet. Dev. 10, 94–99.10679383
Shirley, E. (1977). A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics 33, 386–389.884197
Smith, M.T. (1996). The mechanism of benzene-induced leukemia: A hypothesis and speculations on the causes of leukemia. Environ. Health Perspect. 104 (Suppl. 6), 1219–1225.9118896
Snyder, C.A., Goldstein, B.D., Sellakumar, A.R., Bromberg, I., Laskin, S., and Albert, R.E. (1980). The inhalation toxicology of benzene: Incidence of hematopoietic neoplasms and hematotoxicity in ARK/J and C57BL/6J mice. Toxicol. Appl. Pharmacol. 54, 323–331.6893503
Snyder, C.A., Goldstein, B.D., Sellakumar, A., Bromberg, I., Laskin, S., and Albert, R.E. (1982). Toxicity of chronic benzene inhalation: CD-1 mice exposed to 300 ppm. Bull. Environ. Contam. Toxicol. 29, 385–391.7171847
Snyder, C.A., Goldstein, B.D., Sellakumar, A.R., and Albert, R.E. (1984). Evidence for hematotoxicity and tumorigenesis in rats exposed to 100 ppm benzene. Am. J. Ind. Med. 5, 429–434.6731444
Sotillo, R., Garcia, J.F., Ortega, S., Martin, J., Dubus, P., Barbacid, M., and Malumbres, M. (2001). Invasive melanoma in Cdk4-targeted mice. Proc. Natl. Acad. Sci. U.S.A. 98, 13,312–13,317.
Soto, J.L., Cabrera, C.M., Serrano, S., and López-Nevot, M.Á. (2005). Mutation analysis of genes that control the G1/S cell cycle in melanoma: TP53, CDKN1A, CDKN2A, and CDKN2B. BMC Cancer 5, 36.15819981
Spalding, J.W., French, J.E., Tice, R.R., Furedi-Machacek, M., Haseman, J.K., and Tennant, R.W. (1999). Development of a transgenic mouse model for carcinogenesis bioassays: Evaluation of chemically induced skin tumors in Tg.AC mice. Toxicol. Sci. 49, 241–254.10416269
Svirbely, J., Dunn, R., and von Oettingen, W. (1943). The acute toxicity of vapors of certain solvents containing appreciable amounts of benzene and toluene. J. Ind. Hyg. Toxicol. 25, 366–373.
Tarone, R.E. (1975). Tests for trend in life table analysis. Biometrika 62, 679–682.
Tennant, R.W., French, J.E., and Spalding, J.W. (1995). Identifying chemical carcinogens and assessing potential risk in short-term bioassays using transgenic mouse models. Environ. Health Perspect. 103, 942–950.8529591
Tice, R.R., Costa, D.L., and Drew, R.T. (1980). Cytogenetic effects of inhaled benzene in murine bone marrow: Induction of sister chromatid exchanges, chromosomal aberrations, and cellular proliferation inhibition in DBA/2 mice. Proc. Natl. Acad. Sci. U.S.A. 77, 2148–2152.6929542
Tsutsui, T., Hayashi, N., Maizumi, H., Huff, J., and Barrett, J.C. (1997). Benzene-, catechol-, hydroquinoneand phenol-induced cell transformation, gene mutations, chromosome aberrations, aneuploidy, sister chromatid exchanges and unscheduled DNA synthesis in Syrian hamster embryo cells. Mutat. Res. 373, 113–123.9015160
United States Environmental Protection Agency (USEPA) (1997). Chemical and Radiation Leukemogenesis in Humans and Rodents and the Value of Rodent Models for Assessing Risks of Lymphohematopoietic Cancers EPA/600/R-97/090. U.S. Environmental Protection Agency, Office of Research and Development, National Center for Environmental Assessment, Washington Office, Washington, DC. <http://cfpub.epa.gov/ncea/cfm/recordisplay.cfm?deid=12181>.
United States Environmental Protection Agency (USEPA) (1998). Carcinogenic Effects of Benzene: An Update (Final) EPA/600/P-97/001F. U.S. Environmental Protection Agency, Office of Research and Development, National Center for Environmental Assessment, Washington Office, Washington, DC. <http://cfpub.epa.gov/ncea/cfm/recordisplay.cfm?deid=2806>.
United States Environmental Protection Agency (USEPA) (2002). Toxicological Review of Benzene (Noncancer Effects) EPA/635/R-02/001F. U.S. Environmental Protection Agency, Office of Research and Development, National Center for Environmental Assessment, Washington Office, Washington, DC. <http://cfpub.epa.gov/ncea/cfm/recordisplay.cfm?deid=51760>.
Waidyanatha, S., and Rappaport, S.M. (2005). Investigation of cysteinyl protein adducts of benzene diolepoxide. Chem. Biol. Interact. 153–154, 261–266.
Waters, M.D., Stack, H.F., Brady, A.L., Lohman, P.H.M., Haroun, L., and Vainio, H. (1988). Use of computerized data listings and activity profiles of genetic and related effects in the review of 195 compounds. Mutat. Res. 205, 295–312.3367921
Whysner, J. (2000). Benzene-induced genotoxicity. J. Toxicol. Environ. Health A 61, 347–351.11086938
Williams, D.A. (1971). A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics 27, 103–117.5547548
Williams, D.A. (1972). The comparison of several dose levels with a zero dose control. Biometrics 28, 519–531.5037867
Williams, D.A. (1986). A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics 42, 183–186.3719054
Witt, K.L., Knapton, A., Wehr, C.M., Hook, G.J., Mirsalis, J., Shelby, M.D., and MacGregor, J.T. (2000). Micronucleated erythrocyte frequency in peripheral blood of B6C3F_1_ mice from short-term, prechronic, and chronic studies of the NTP Carcinogenesis Bioassay Program. Environ. Mol. Mutagen. 36, 163–194.11044899
Wolf, M., Rowe, V., McCollister, D., Hollingsworth, R., and Oyen, F. (1956). Toxicological studies of certain alkylated benzenes and benzene. AMA Arch. Ind. Health 14, 387–398.13361560
World Health Organization (WHO) (1993). Benzene. Environmental Health Criteria 150. World Health Organization, Geneva.
Yoon, B.I., Li, G.X., Kitada, K., Kawasaki, Y., Igarashi, K., Kodama, Y., Inoue, T., Kobayashi, K., Kanno, J., Kim, D.Y., Inoue, T., and Hirabayashi, Y. (2003). Mechanisms of benzene-induced hematotoxicity and leukemogenicity: cDNA microarray analyses using mouse bone marrow tissue. Environ. Health Perspect. 111, 1411–1420.12928149
Zeiger, E., and Haworth, S. (1985). Tests with a preincubation modification of the Salmonella/microsome assay. In Progress in Mutation Research; Evaluation of Short-term Tests for Carcinogens; Report of the International Programme on Chemical Safety’s Collaborative Study on In vitro Assays (J. Ashby, F.J. de Serres, M. Draper, M. Ishidate, Jr., B.H. Margolin, B.E. Matter, and M.D. Shelby, Eds.), Vol. 5, pp. 187–199. Elsevier Science Publishers, Amsterdam.
Zhang, L., Rothman, N., Wang, Y., Hayes, R.B., Yin, S., Titenko-Holland, N., Dosemeci, M., Wang, Y.-Z., Kolachana, P., Lu, W., Xi, L., Li, G.-L., and Smith, M.T. (1999). Benzene increases aneuploidy in the lymphocytes of exposed workers: A comparison of data obtained by fluorescence in situ hybridization in interphase and metaphase cells. Environ. Mol. Mutagen. 34, 260–268.10618174