# MATERIALS AND METHODS

## Procurement and Characterization of Benzene

Benzene was obtained from Sigma Aldrich Chemical Co. (Milwaukee, WI) in one lot (00358CS). Identity and purity analyses were conducted by the analytical chemistry laboratory, Research Triangle Institute (RTI) (Research Triangle Park, NC) and the study laboratory, Battelle Columbus Operations (Columbus, OH) (Appendix D). Reports on analyses performed in support of the benzene study are on file at the National Institute of Environmental Health Sciences.

Lot 00358CS, a colorless liquid, was identified as benzene by RTI using infrared spectroscopy and proton nuclear magnetic resonance (NMR) spectroscopy and by the study laboratory using infrared spectroscopy. Spectra were in agreement with the structure of benzene, literature spectra (Aldrich, 1981, 1983, 1985), and spectra from a frozen reference standard of the same lot.

The purity of lot 00358CS was determined by RTI and by the study laboratory using gas chromatography (GC) by flame ionization. The purity profile performed by RTI detected one major peak and one impurity peak with an area that was less than 0.1% of the total peak area. The overall purity of lot 00358CS was determined to be greater than 99%.

To ensure stability, the bulk chemical was stored at room temperature (25° C) in amber glass bottles with Teflon^®^-lined lids, protected from light. Stability was monitored twice during the 27-week study with GC by flame ionization; no degradation of the bulk chemical was detected. The purity profile performed by the study laboratory detected one major peak with a purity of 99.3% relative to a frozen reference standard of the same lot.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared by mixing benzene with corn oil (Spectrum Chemicals and Laboratory Products, Inc., Gardena, CA) to give the required concentrations. Because animal room sample analyses indicated probable evaporative loss of benzene from the dose formulations during administration, dose formulations prepared on January 4, 2000, or later were prepared with 5% less corn oil than specified in the original SOP for dose formulation. The dose formulations were stored at room temperature (25° C) in amber glass bottles capped with Teflon^®^-lined lids for up to 35 days.

Stability studies of a 1.0 mg/mL dose formulation of benzene in corn oil were performed by RTI with GC by flame ionization. Stability was confirmed for up to 35 days for dose formulations stored in the dark in sealed glass bottles at refrigerator temperature (5° C) and for up to 3 hours exposed to air and light under simulated dosing conditions.

Periodic analyses of the dose formulations of benzene were conducted by the study laboratory using GC by flame ionization. During the 27-week study, the dose formulations were analyzed four times and postadministration animal room samples were analyzed once (Table D3). All 12 dose formulations analyzed and used in the study were within 10% of the target concentrations; all four animal room samples analyzed were within 15% of the target concentration. Periodic analyses of the corn oil vehicle by the study laboratory demonstrated peroxide concentrations below the acceptable limit of 3 mEq/kg.

## 27-Week Study

### Study Design

Groups of 15 male and 15 female mice were administered benzene in corn oil by gavage at doses of 0, 25, 50, 100, or 200 mg benzene/kg body weight 5 days per week for 27 weeks. The doses selected for use in the 27-week study were chosen to overlap those used for p53^+/−^ mice in the French et al. (2001) gavage study and for B6C3F_1_ mice in the NTP (1986) 2-year gavage study.

### Source and Specification of Animals

Male and female heterozygous B6.129-Cdkn2a^tm1Rdp^ N3 (i.e., haploinsufficient p16^Ink4a^/p19^Arf^) mice were obtained from Taconic Laboratory Animals and Services (Germantown, NY) for use in the 27-week study. The N1 male mice homozygous null for the Cdkn2a deletion were backcrossed to inbred C57BL/6 females from Taconic Laboratory to produce male and female B6.129-Cdkn2^atm1Rdp^ haploinsufficient or p16^Ink4a^/p19^Arf+/−^ mice (Serrano et al., 1996). The genetic background of these mice was: 80% C57BL/6, 19% 129/Sv, and 1% SJL. This line, designated 5003 by Taconic Laboratory, was embryo cryopreserved in 2003. Upon receipt, the mice were 3 to 4 weeks old. Animals were quarantined for 22 days and were 7 to 8 weeks old on the first day of the study. Before the study began, five male and five female mice were randomly selected for parasite evaluation and gross observation for evidence of disease. Blood samples were collected from up to five male and five female sentinel animals at 4 weeks and at study termination. The sera were analyzed for antibody titers to rodent viruses (Boorman et al., 1986; Rao et al., 1989a,b). All results were negative.

Mice were housed individually. Feed and water were available ad libitum. Cages and racks were rotated weekly. Further details of animal maintenance are given in Table 2.

### Clinical Examinations and Pathology

All mice were observed twice daily. Clinical findings were recorded weekly, to coincide with body weight collection, and at the end of the study. The mice were weighed initially, weekly, and at the end of the study.

Blood for hematology analysis was collected from the retroorbital sinus of mice under carbon dioxide anesthesia at 13 and 27 weeks. Samples were placed in micro-collection tubes (Sarstedt, Inc., Nümbrecht, Germany) coated with potassium EDTA. Hematocrit; erythrocyte, platelet, and leukocyte counts; mean cell hemoglobin; and mean cell hemoglobin concentration were determined with a Cell-Dyn^®^ hematology analyzer (Abbott Laboratories, Abbott Park, IL). Differential leukocyte counts were determined microscopically from smears stained with a Wright-Giemsa stain. A Miller Disc was used to determine reticulocyte counts from smears prepared with blood stained with new methylene blue.

Complete necropsies and microscopic examinations were performed on all mice. The heart, right kidney, liver, lung, right testis, and thymus were weighed. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. Table 2 lists the tissues and organs routinely examined.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The slides, paraffin blocks, and residual wet tissues were sent to the NTP Archives for inventory, slide/block match, and wet tissue audit. The slides, individual animal data records, and pathology tables were evaluated by an independent quality assessment laboratory. The individual animal records and tables were compared for accuracy; the slide and tissue counts were verified, and the histotechnique was evaluated. For the 27-week study, a quality assessment pathologist evaluated slides from all tumors and all potential target organs, which included the bone marrow, lymph nodes, skin, spleen, and thymus.

The quality assessment report and the reviewed slides were submitted to the NTP Pathology Working Group (PWG) chairperson, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and quality assessment pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and quality assessment pathologists, or lesions of general interest were presented by the PWG chairperson to the NTP pathologist. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), the PWG chairperson, and the NTP pathologist. Details of these review procedures have been described, in part, by Maronpot and Boorman (1982) and Boorman et al. (1985). For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al. (1986).

TABLE 2 Experimental Design and Materials and Methods in the 27-Week Gavage Study of Benzene

Study Laboratory
Battelle Columbus Operations (Columbus, OH)
Strain and Species
Haploinsufficient p16^Ink4a^/p19^Arf^ Mice (Heterozygous B6.129-Cdkn2a^tm1Rdp^ N3)
Animal Source
Taconic Laboratory Animals and Services (Germantown, NY)
Time Held Before Study
22 days
Average Age When Studies Began
7 to 8 weeks
Date of First Dose
October 29, 1999
Duration of Dosing
5 days/week for 27 weeks
Date of Last Dose
May 2–4, 2000
Necropsy Dates
May 3–5, 2000
Average Age at Necropsy
33 to 35 weeks
Size of Study Groups
15 males and 15 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage
1
Method of Animal Identification
Tail tattoo and ear tag
Diet
Irradiated NTP-2000 pelleted feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum
Water
Tap water (City of Columbus municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum
Cages
Polycarbonate (Lab Products, Inc., Maywood, NJ), changed weekly
Racks
Stainless steel (Lab Products, Inc., Maywood, NJ), changed every 2 weeks
Bedding
Irradiated Sani-Chips^®^ (P.J. Murphy Forest Products Corp., Montville, NJ), changed weekly
Cage Filters
DuPont 2024 spun-bonded polyester (Snow Filtration Co., Cincinnati, OH), changed every 2 weeks
Animal Room Environment
Temperature: 72° ± 3° F
Relative humidity: 50% ± 15%
Room fluorescent light: 12 hours/day
Room air changes: at least 10/hour
Doses
0, 25, 50, 100, or 200 mg/kg in corn oil (dosing volume 10 mL/kg body weight)
Type and Frequency of Observation
Observed twice daily; animals were weighed initially, weekly, and at the end of the study; clinical findings were recorded weekly.
Method of Sacrifice
CO_2_ asphyxiation
Necropsy
Necropsies were performed on all animals. Organs weighed were heart, right kidney, liver, lungs, right testis, and thymus.
Clinical Pathology
Blood was collected via the retroorbital sinus from all animals during weeks 13 and 27 for hematology.
Hematology: hematocrit; hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials
Histopathology
Histopathology was performed on all mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow (femur and sternum), brain, clitoral gland, large intestine (colon, cecum, rectum), small intestine (duodenum, ileum, jejunum), heart, kidney, liver, lung, lymph nodes (mandibular, mesenteric), mammary gland, ovary, pituitary gland, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, urinary bladder, and uterus.

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier (1958). Animals found dead of other than natural causes were censored; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s (1972) method for testing two groups for equality and Tarone’s (1975) life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented in Tables A1, A2, A3, and A4 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test (Gart et al., 1979) and the Cochran-Armitage trend test (Armitage, 1971; Gart et al., 1979), procedures based on the overall proportion of affected animals, were used to determine significance.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett (1955) and Williams (1971, 1972). Hematology data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley (1977) (as modified by Williams, 1986) and Dunn (1964). Jonckheere’s test (Jonckheere, 1954) was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey (1957) were examined by NTP personnel, and implausible values were eliminated from the analysis. Average severity values were analyzed for significance with the Mann-Whitney U test (Hollander and Wolfe, 1973).

## Quality Assurance Methods

The 27-week study was conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations (21 CFR, Part 58). In addition, as records were submitted to the NTP Archives, this study was audited retrospectively by an independent quality assurance contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Report.

## Genetic Toxicology

### Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al. (1990). At 6.5, 13, 19.5, and 27 weeks, peripheral blood samples were obtained from male and female haploinsufficient p16^Ink4a^/p19^Arf^ mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 2,000 normochromatic erythrocytes (NCEs) in each of up to 15 animals per dose group. In addition, the percentage of polychromatic erythrocytes among 1,000 total erythrocytes was determined for each animal as a measure of benzene-induced bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group, plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over dose groups using a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each dosed group and the vehicle control group (ILS, 1990). In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single dosed group is less than or equal to 0.025 divided by the number of dosed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects. Because these studies were not repeated, the results of the micronucleus trials were accepted without replication.