# APPENDIX C ORGAN WEIGHTS AND ORGAN-WEIGHT-TO-BODY-WEIGHT RATIOS

TABLE C1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 27-Week Gavage Study of Benzene^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
Male
n | 15 | 15 | 15 | 15 | 14
Necropsy body wt | 44.0 ± 1.4 | 38.3 ± 1.4^**^ | 38.0 ± 1.0^**^ | 31.7 ± 1.2^**^ | 32.4 ± 0.8^**^
Heart
Absolute | 0.204 ± 0.005 | 0.191 ± 0.005 | 0.194 ± 0.006 | 0.186 ± 0.008 | 0.183 ± 0.007
Relative | 4.684 ± 0.136 | 5.044 ± 0.165 | 5.148 ± 0.213 | 5.888 ± 0.182^**^ | 5.652 ± 0.174^**^
R. Kidney
Absolute | 0.307 ± 0.009 | 0.322 ± 0.006 | 0.315 ± 0.008 | 0.304 ± 0.009 | 0.302 ± 0.005
Relative | 7.006 ± 0.123 | 8.543 ± 0.280^**^ | 8.349 ± 0.207^**^ | 9.685 ± 0.279^**^ | 9.367 ± 0.193^**^
Liver
Absolute | 1.940 ± 0.094 | 1.638 ± 0.062^**^ | 1.644 ± 0.045^**^ | 1.468 ± 0.077^**^ | 1.599 ± 0.034^**^
Relative | 43.893 ± 0.932 | 42.907 ± 0.937 | 43.413 ± 0.966 | 46.087 ± 1.229 | 49.564 ± 0.871^**^
Lung
Absolute | 0.251 ± 0.008 | 0.245 ± 0.006 | 0.244 ± 0.006 | 0.236 ± 0.008 | 0.237 ± 0.006
Relative | 5.767 ± 0.211 | 6.540 ± 0.289^*^ | 6.492 ± 0.228^*^ | 7.509 ± 0.196^**^ | 7.387 ± 0.276^**^
R. Testis
Absolute | 0.119 ± 0.003 | 0.116 ± 0.002 | 0.111 ± 0.002^*^ | 0.104 ± 0.003^**^ | 0.097 ± 0.002^**^
Relative | 2.734 ± 0.105 | 3.072 ± 0.083^*^ | 2.949 ± 0.074 | 3.326 ± 0.091^**^ | 3.028 ± 0.101
Thymus
Absolute | 0.051 ± 0.005 | 0.039 ± 0.003^**^ | 0.031 ± 0.002^**^ | 0.019 ± 0.002^**^ | 0.021 ± 0.004^**^
Relative | 1.154 ± 0.078 | 1.028 ± 0.057 | 0.821 ± 0.044^**^ | 0.587 ± 0.057^**^ | 0.654 ± 0.109^**^
Females
n | 15 | 15 | 15 | 15 | 15
Necropsy body wt | 29.8 ± 1.4 | 28.5 ± 0.9 | 29.0 ± 0.5 | 28.7 ± 1.0 | 26.8 ± 0.5
Heart
Absolute | 0.156 ± 0.004 | 0.149 ± 0.003 | 0.149 ± 0.003 | 0.152 ± 0.003 | 0.152 ± 0.003
Relative | 5.352 ± 0.208 | 5.270 ± 0.151 | 5.159 ± 0.118 | 5.363 ± 0.154 | 5.688 ± 0.097
R. Kidney
Absolute | 0.224 ± 0.008 | 0.227 ± 0.005 | 0.238 ± 0.003 | 0.227 ± 0.006 | 0.231 ± 0.004
Relative | 7.631 ± 0.221 | 8.025 ± 0.148 | 8.241 ± 0.147 | 7.972 ± 0.225 | 8.660 ± 0.203^**^
Liver
Absolute | 1.381 ± 0.058 | 1.353 ± 0.038 | 1.376 ± 0.036 | 1.327 ± 0.047 | 1.309 ± 0.027
Relative | 46.715 ± 1.151 | 47.756 ± 1.129 | 47.528 ± 1.110 | 46.357 ± 1.114 | 49.028 ± 1.066
Lung
Absolute | 0.236 ± 0.005 | 0.232 ± 0.005 | 0.220 ± 0.005 | 0.226 ± 0.005 | 0.219 ± 0.004
Relative | 8.069 ± 0.272 | 8.222 ± 0.235 | 7.628 ± 0.206 | 7.951 ± 0.204 | 8.224 ± 0.182
Thymus
Absolute | 0.038 ± 0.003 | 0.040 ± 0.002 | 0.033 ± 0.002 | 0.032 ± 0.003 | 0.032 ± 0.001
Relative | 1.293 ± 0.072 | 1.407 ± 0.079 | 1.155 ± 0.089 | 1.111 ± 0.072 | 1.183 ± 0.054

* Significantly different (P≤0.05) from the vehicle control group by Williams’ or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).