# APPENDIX B CLINICAL PATHOLOGY RESULTS

TABLE B1 Hematology Data for Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 27-Week Gavage Study of Benzene^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
Male
n
Week 13 | 15 | 15 | 15 | 15 | 14
Week 27 | 15 | 15 | 15 | 15 | 13
Hematocrit (%)
Week 13 | 51.5 ± 0.5 | 50.2 ± 0.7 | 47.3 ± 0.6^**^ | 44.3 ± 0.6^**^ | 40.9 ± 0.9^**^
Week 27 | 48.4 ± 0.4 | 47.1 ± 0.9 | 44.8 ± 0.5^**^ | 43.5 ± 0.7^**^ | 36.4 ± 1.3^**^
Hemoglobin (g/dL)
Week 13 | 17.1 ± 0.1 | 16.4 ± 0.2^**^ | 15.4 ± 0.2^**^ | 14.6 ± 0.3^**^ | 13.4 ± 0.3^**^
Week 27 | 16.3 ± 0.2 | 15.8 ± 0.3 | 15.2 ± 0.2^**^ | 14.4 ± 0.2^**^ | 12.1 ± 0.4^**^
Erythrocytes (10^6^/μL)
Week 13 | 11.51 ± 0.11 | 10.74 ± 0.16^**^ | 10.04 ± 0.15^**^ | 9.14 ± 0.14^**^ | 8.31 ± 0.22^**^
Week 27 | 10.92 ± 0.12 | 10.20 ± 0.20^*^ | 9.55 ± 0.12^**^ | 8.99 ± 0.16^**^ | 7.11 ± 0.27^**^
Reticulocytes (10^5^/μL)
Week 13 | 2.19 ± 0.20 | 1.85 ± 0.14 | 1.57 ± 0.14^*^ | 1.42 ± 0.18^**^ | 1.38 ± 0.17^**^
Week 27 | 1.89 ± 0.15 | 1.99 ± 0.21 | 2.61 ± 0.10^**^ | 3.16 ± 0.29^**^ | 2.99 ± 0.35^**^
Nucleated erythrocytes (10^3^/μL)
Week 13 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00^**^
Week 27 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL)
Week 13 | 44.8 ± 0.2 | 46.7 ± 0.2^**^ | 47.1 ± 0.2^**^ | 48.6 ± 0.2^**^ | 49.4 ± 0.3^**^
Week 27 | 44.3 ± 0.3 | 46.2 ± 0.2^**^ | 46.9 ± 0.2^**^ | 48.4 ± 0.3^**^ | 51.4 ± 0.7^**^
Mean cell hemoglobin (pg)
Week 13 | 14.8 ± 0.1 | 15.3 ± 0.1^**^ | 15.4 ± 0.1^**^ | 16.0 ± 0.1^**^ | 16.2 ± 0.2^**^
Week 27 | 15.0 ± 0.2 | 15.5 ± 0.1^**^ | 15.9 ± 0.2^**^ | 16.0 ± 0.1^**^ | 17.0 ± 0.2^**^
Mean cell hemoglobin concentration (g/dL)
Week 13 | 33.2 ± 0.2 | 32.7 ± 0.1 | 32.7 ± 0.1 | 32.9 ± 0.3 | 32.8 ± 0.3
Week 27 | 33.8 ± 0.4 | 33.6 ± 0.2 | 33.9 ± 0.3 | 33.0 ± 0.1 | 33.1 ± 0.1
Platelets (10^3^/μL)
Week 13 | 819.2 ± 20.4 | 795.9 ± 35.3 | 857.2 ± 39.5 | 730.1 ± 26.4^*^ | 644.4 ± 32.6^**^
Week 27 | 944.6 ± 38.5 | 909.5 ± 39.9 | 852.3 ± 37.2 | 816.8 ± 45.3 | 784.1 ± 39.7^**^
Leukocytes (10^3^/μL)
Week 13 | 4.20 ± 0.42 | 2.79 ± 0.24^*^ | 2.38 ± 0.15^**^ | 1.42 ± 0.07^**^ | 0.93 ± 0.08^**^
Week 27 | 5.25 ± 0.41 | 3.19 ± 0.27^**^ | 2.21 ± 0.18^**^ | 1.48 ± 0.15^**^ | 0.95 ± 0.06^**^
Segmented neutrophils (10^3^/μL)
Week 13 | 0.45 ± 0.05 | 0.41 ± 0.05 | 0.43 ± 0.05 | 0.41 ± 0.03 | 0.33 ± 0.03
Week 27 | 1.10 ± 0.14 | 0.81 ± 0.09 | 0.81 ± 0.12^*^ | 0.60 ± 0.11^**^ | 0.52 ± 0.04^**^
Bands (10^3^/μL)
Week 13 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 27 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL)
Week 13 | 3.70 ± 0.39 | 2.33 ± 0.19^*^ | 1.93 ± 0.12^**^ | 0.99 ± 0.06^**^ | 0.59 ± 0.07^**^
Week 27 | 4.12 ± 0.43 | 2.35 ± 0.23^**^ | 1.38 ± 0.08^**^ | 0.87 ± 0.09^**^ | 0.42 ± 0.03^**^
Monocytes (10^3^/μL)
Week 13 | 0.02 ± 0.01 | 0.02 ± 0.01 | 0.01 ± 0.00 | 0.02 ± 0.01 | 0.01 ± 0.00
Week 27 | 0.02 ± 0.01 | 0.01 ± 0.01 | 0.01 ± 0.00 | 0.01 ± 0.01 | 0.00 ± 0.00
Basophils (10^3^/μL)
Week 13 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 27 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL)
Week 13 | 0.04 ± 0.01 | 0.03 ± 0.01 | 0.01 ± 0.00^*^ | 0.00 ± 0.00^**^ | 0.00 ± 0.00^*^
Week 27 | 0.02 ± 0.01 | 0.02 ± 0.01 | 0.01 ± 0.00 | 0.01 ± 0.00 | 0.00 ± 0.00
Female
n
Week 13 | 15 | 15 | 15 | 14 | 15
Week 27 | 15 | 15 | 15 | 14 | 14
Hematocrit (%)
Week 13 | 50.1 ± 0.5 | 50.2 ± 0.6 | 48.8 ± 0.6 | 47.4 ± 1.1^*^ | 46.7 ± 0.8^**^
Week 27 | 45.5 ± 0.5 | 45.6 ± 0.8 | 46.0 ± 0.8 | 44.3 ± 0.8 | 42.9 ± 0.5^**^
Hemoglobin (g/dL)
Week 13 | 17.0 ± 0.2 | 16.7 ± 0.2 | 16.4 ± 0.2 | 15.8 ± 0.4^**^ | 15.7 ± 0.3^**^
Week 27 | 15.5 ± 0.2 | 15.4 ± 0.3 | 15.5 ± 0.3 | 14.9 ± 0.3 | 14.2 ± 0.2^**^
Erythrocytes (10^6^/μL)
Week 13 | 10.94 ± 0.12 | 10.83 ± 0.13 | 10.52 ± 0.13^*^ | 9.92 ± 0.26^**^ | 9.80 ± 0.17^**^
Week 27 | 10.02 ± 0.11 | 10.02 ± 0.21 | 10.04 ± 0.20 | 9.41 ± 0.17^**^ | 9.03 ± 0.11^**^
Reticulocytes (10^5^/μL)
Week 13 | 2.03 ± 0.15 | 1.79 ± 0.16 | 1.99 ± 0.14 | 2.18 ± 0.36 | 1.74 ± 0.19
Week 27 | 1.33 ± 0.12 | 1.24 ± 0.07 | 1.25 ± 0.15 | 1.57 ± 0.14 | 1.67 ± 0.14
Nucleated erythrocytes (10^3^/μL)
Week 13 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 27 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL)
Week 13 | 45.8 ± 0.2 | 46.4 ± 0.2^*^ | 46.4 ± 0.1^*^ | 47.9 ± 0.2^**^ | 47.7 ± 0.2^**^
Week 27 | 45.4 ± 0.2 | 45.6 ± 0.3 | 45.9 ± 0.2 | 47.1 ± 0.2^**^ | 47.5 ± 0.2^**^
Mean cell hemoglobin (pg)
Week 13 | 15.5 ± 0.1 | 15.4 ± 0.1 | 15.6 ± 0.1 | 16.0 ± 0.1^**^ | 16.0 ± 0.1^**^
Week 27 | 15.5 ± 0.1 | 15.4 ± 0.1 | 15.4 ± 0.1 | 15.8 ± 0.1^*^ | 15.7 ± 0.1^*^
Mean cell hemoglobin concentration (g/dL)
Week 13 | 33.9 ± 0.1 | 33.2 ± 0.1^**^ | 33.7 ± 0.1 | 33.4 ± 0.1^*^ | 33.6 ± 0.2
Week 27 | 34.1 ± 0.1 | 33.7 ± 0.1^*^ | 33.6 ± 0.1^*^ | 33.6 ± 0.1^*^ | 33.2 ± 0.1^**^
Platelets (10^3^/μL)
Week 13 | 698.3 ± 21.2 | 618.8 ± 24.2 | 681.6 ± 22.9 | 629.6 ± 30.4 | 623.5 ± 29.1
Week 27 | 748.3 ± 39.9 | 743.9 ± 37.6 | 802.1 ± 42.8 | 725.5 ± 48.8 | 703.9 ± 53.2
Leukocytes (10^3^/μL)
Week 13 | 5.07 ± 0.50 | 4.84 ± 0.35 | 3.59 ± 0.22^*^ | 3.28 ± 0.16^**^ | 3.83 ± 0.31^*^
Week 27 | 6.25 ± 0.36 | 6.17 ± 0.48 | 4.71 ± 0.29^**^ | 3.41 ± 0.24^**^ | 3.74 ± 0.34^**^
Segmented neutrophils (10^3^/μL)
Week 13 | 0.51 ± 0.06 | 0.44 ± 0.04 | 0.41 ± 0.03 | 0.46 ± 0.04 | 0.74 ± 0.06^*^
Week 27 | 0.71 ± 0.11 | 1.06 ± 0.21 | 1.06 ± 0.14 | 0.79 ± 0.09 | 0.96 ± 0.19
Bands (10^3^/μL)
Week 13 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 27 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL)
Week 13 | 4.53 ± 0.45 | 4.35 ± 0.33 | 3.13 ± 0.19^*^ | 2.77 ± 0.15^**^ | 3.03 ± 0.26^**^
Week 27 | 5.48 ± 0.32 | 5.03 ± 0.37 | 3.56 ± 0.18^**^ | 2.57 ± 0.21^**^ | 2.69 ± 0.22^**^
Monocytes (10^3^/μL)
Week 13 | 0.01 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.04 ± 0.01
Week 27 | 0.04 ± 0.01 | 0.03 ± 0.01 | 0.05 ± 0.01 | 0.02 ± 0.01 | 0.04 ± 0.02
Basophils (10^3^/μL)
Week 13 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 27 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/μL)
Week 13 | 0.02 ± 0.01 | 0.02 ± 0.01 | 0.03 ± 0.01 | 0.02 ± 0.01 | 0.03 ± 0.01
Week 27 | 0.02 ± 0.01 | 0.05 ± 0.01 | 0.04 ± 0.02 | 0.03 ± 0.01 | 0.04 ± 0.01

* Significantly different (P≤0.05) from the vehicle control group by Dunn’s or Shirley’ test

** P≤0.01

a Data are given as mean ± standard error. Statistical tests were performed on unrounded data.