# APPENDIX A SUMMARY OF LESIONS IN HAPLOINSUFFICIENT p16^Ink4a^/p19^Arf^ MICE IN THE 27-WEEK GAVAGE STUDY OF BENZENE

TABLE A1 Summary of the Incidence of Neoplasms in Male Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 27-Week Gavage Study of Benzene^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | | | | | 1
Survivors
Terminal sacrifice | 15 | 15 | 15 | 15 | 14
Animals examined microscopically | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15) | (15)
Stomach, forestomach | (15) | (15) | (15) | (15) | (15)
Cardiovascular System
Heart | (15) | (15) | (15) | (15) | (15)
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15) | (15)
Thyroid gland | (15) | (15) | (15) | (15) | (15)
General Body System
None
Genital System
Epididymis | (15) | (15) | (15) | (15) | (15)
Testes | (15) | (15) | (15) | (15) | (15)
Hematopoietic System
Bone marrow | (15) | (15) | (15) | (15) | (15)
Lymph node | (11) | (11) | (12) | (9) | (7)
Lymph node, mandibular | (15) | (15) | (15) | (14) | (14)
Lymph node, mesenteric | (15) | (15) | (14) | (15) | (15)
Spleen | (15) | (15) | (15) | (15) | (15)
Thymus | (15) | (15) | (15) | (15) | (15)
Integumentary System
None
Musculoskeletal System
None
Nervous System
Brain | (15) | (15) | (15) | (15) | (15)
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15)
Special Senses System
Eye | | | | | (1)
Urinary System
Kidney | (15) | (15) | (15) | (15) | (15)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15) | (15)
Lymphoma malignant | | | | | 5 (33%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | | | | | 5
Total primary neoplasms | | | | | 5
Total animals with malignant neoplasms | | | | | 5
Total malignant neoplasms | | | | | 5

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A2 Summary of the Incidence of Nonneoplastic Lesions in Male Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 27-Week Gavage Study of Benzene^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | | | | | 1
Survivors
Terminal sacrifice | 15 | 15 | 15 | 15 | 14
Animals examined microscopically | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15) | (15)
Inflammation, chronic | 3 (20%) | 6 (40%) | 1 (7%) | 3 (20%) | 1 (7%)
Salivary glands | | | | (1) | (1)
Submandibular gland, atrophy | | | | | 1 (100%)
Submandibular gland, inflammation, chronic | | | | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15) | (15)
Erosion | | | | | 1 (7%)
Hyperplasia | 1 (7%) | | | | 3 (20%)
Inflammation, acute | | | | 1 (7%)
Stomach, glandular | (15) | (15) | (15) | (15) | (15)
Mineralization | | | 1 (7%)
Glands, cyst | | | 1 (7%) | 1 (7%)
Cardiovascular System
Heart | (15) | (15) | (15) | (15) | (15)
Myocardium, inflammation, chronic | | 1 (7%) | 1 (7%)
Endocrine System
None
General Body System
None
Genital System
Epididymis | (15) | (15) | (15) | (15) | (15)
Granuloma sperm | | | | | 1 (7%)
Unilateral, hypospermia | 1 (7%)
Testes | (15) | (15) | (15) | (15) | (15)
Germinal epithelium, atrophy | | | | 1 (7%)
Germinal epithelium, syncytial alteration | | | | 1 (7%) | 1 (7%)
Rete testes, inflammation, granulomatous | 1 (7%)
Unilateral, germinal epithelium, atrophy | 1 (7%)
Hematopoietic System
Bone marrow | (15) | (15) | (15) | (15) | (15)
Atrophy | | | | 10 (67%) | 12 (80%)
Pigmentation, hemosiderin | 1 (7%) | 13 (87%) | 13 (87%) | 15 (100%) | 14 (93%)
Lymph node | (11) | (11) | (12) | (9) | (7)
Mediastinal, atrophy | | | 2 (17%) | 6 (67%) | 6 (86%)
Lymph node, mandibular | (15) | (15) | (15) | (14) | (14)
Atrophy | | | | 6 (43%) | 11 (79%)
Hyperplasia, lymphoid | 2 (13%) | 1 (7%) | 1 (7%)
Infiltration cellular, polymorphonuclear | | | | 1 (7%) | 1 (7%)
Lymph node, mesenteric | (15) | (15) | (14) | (15) | (15)
Atrophy | 1 (7%) | 2 (13%) | 2 (14%) | 13 (87%) | 13 (87%)
Infiltration cellular, polymorphonuclear | | | | | 1 (7%)
Spleen | (15) | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | 1 (7%) | | 2 (13%) | 8 (53%)
Lymphoid follicle, atrophy | | | | 15 (100%) | 14 (93%)
Thymus | (15) | (15) | (15) | (15) | (15)
Atrophy | | | | 7 (47%) | 13 (87%)
Mineralization | | | | | 1 (7%)
Integumentary System
Skin | (15) | (15) | (15) | (15) | (15)
Pigmentation | | 15 (100%) | 15 (100%) | 15 (100%) | 14 (93%)
Musculoskeletal System
Bone | (15) | (15) | (15) | (15) | (15)
Pigmentation, hemosiderin | | | 1 (7%)
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15)
Inflammation, chronic active | 2 (13%) | | 1 (7%) | 3 (20%) | 5 (33%)
Alveolar epithelium, hyperplasia, focal | | | 1 (7%)
Bronchiole, hyperplasia, focal | | | 1 (7%)
Special Senses System
None
Urinary System
Kidney | (15) | (15) | (15) | (15) | (15)
Casts protein | 1 (7%) | | 2 (13%) | 1 (7%) | 2 (13%)
Nephropathy | 1 (7%) | 1 (7%) | | 2 (13%) | 4 (27%)

a Number of animals examined microscopically at the site and the number of animals with lesion

TABLE A3 Summary of the Incidence of Neoplasms in Female Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 27-Week Gavage Study of Benzene^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15
Survivors
Terminal sacrifice | 15 | 15 | 15 | 15 | 15
Animals examined microscopically | 15 | 15 | 15 | 15 | 15
Alimentary System
None
Cardiovascular System
None
Endocrine System
None
General Body System
None
Genital System
Ovary | (14) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | | 2 (13%)
Hematopoietic System
Bone marrow | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 3 (20%) | 2 (13%) | | | 3 (20%)
Integumentary System
None
Musculoskeletal System
None
Nervous System
None
Respiratory System
None
Special Senses System
None
Urinary System
None
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15) | (15)
Histiocytic sarcoma | 3 (20%) | 3 (20%) | | | 3 (20%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 3 | 3 | | | 3
Total primary neoplasms | 3 | 3 | | | 3
Total animals with malignant neoplasms | 3 | 3 | | | 3
Total malignant neoplasms | 3 | 3 | | | 3

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A4 Summary of the Incidence of Nonneoplastic Lesions in Female Haploinsufficient p16^Ink4a^/p19^Arf^ Mice in the 27-Week Gavage Study of Benzene^a^

| Vehicle Control | 25 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15
Survivors
Terminal sacrifice | 15 | 15 | 15 | 15 | 15
Animals examined microscopically | 15 | 15 | 15 | 15 | 15
Alimentary System
Intestine small, duodenum | (15) | (15) | (15) | (15) | (15)
Inflammation, chronic active | | | | 2 (13%)
Liver | (15) | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | | | | 1 (7%) | 1 (7%)
Inflammation, chronic | 10 (67%) | 6 (40%) | 6 (40%) | 4 (27%) | 11 (73%)
Stomach, forestomach | (15) | (15) | (15) | (15) | (15)
Erosion | | | | 1 (7%)
Hyperplasia | 1 (7%)
Inflammation, chronic | | | 3 (20%)
Stomach, glandular | (15) | (15) | (15) | (15) | (15)
Mineralization | | | | | 1 (7%)
Cardiovascular System
Heart | (15) | (15) | (15) | (15) | (15)
Myocardium, inflammation, chronic | | | | | 1 (7%)
Endocrine System
Pituitary gland | (15) | (15) | (15) | (15) | (15)
Infiltration cellular, lymphoid | 1 (7%)
General Body System
None
Genital System
Clitoral gland | (1)
Pigmentation | 1 (100%)
Ovary | (14) | (15) | (15) | (15) | (15)
Angiectasis | | | | | 1 (7%)
Cyst | 1 (7%) | | | 2 (13%) | 2 (13%)
Uterus | (15) | (15) | (15) | (15) | (15)
Inflammation, chronic active | | | | | 1 (7%)
Inflammation, suppurative | | | 1 (7%) | 1 (7%) | 1 (7%)
Endometrium, hyperplasia, cystic | 12 (80%) | 15 (100%) | 15 (100%) | 15 (100%) | 14 (93%)
Hematopoietic System
Lymph node | (13) | (11) | (11) | (12) | (13)
Lumbar, hyperplasia, lymphoid | | | | | 1 (8%)
Lumbar, pigmentation | | | | | 1 (8%)
Mediastinal, atrophy | | | 2 (18%) | 4 (33%) | 2 (15%)
Lymph node, mandibular | (14) | (15) | (15) | (15) | (15)
Atrophy | | 1 (7%) | 2 (13%) | 4 (27%)
Hyperplasia, lymphoid | 1 (7%) | 4 (27%) | 2 (13%) | 5 (33%) | 3 (20%)
Infiltration cellular, polymorphonuclear | 1 (7%) | | | | 2 (13%)
Lymph node, mesenteric | (15) | (15) | (15) | (15) | (15)
Atrophy | | 2 (13%) | 3 (20%) | 8 (53%) | 6 (40%)
Hyperplasia, lymphoid | | | | | 1 (7%)
Spleen | (15) | (15) | (15) | (15) | (15)
Hematopoietic cell proliferation | 5 (33%) | 5 (33%) | 2 (13%) | 3 (20%) | 7 (47%)
Infiltration cellular, lymphocyte | 1 (7%)
Lymphoid follicle, atrophy | | 1 (7%) | 1 (7%) | | 1 (7%)
Thymus | (15) | (15) | (15) | (15) | (15)
Hyperplasia, atypical | | 1 (7%) | 1 (7%) | 1 (7%) | 1 (7%)
Integumentary System
Mammary gland | (15) | (15) | (15) | (15) | (15)
Hyperplasia | | | | | 2 (13%)
Skin | (15) | (15) | (15) | (15) | (15)
Inflammation, granulomatous | 1 (7%) | | 1 (7%)
Inflammation, suppurative | | | | 1 (7%) | 1 (7%)
Pigmentation | | 1 (7%) | 8 (53%) | 15 (100%) | 15 (100%)
Musculoskeletal System
Bone | (15) | (15) | (15) | (15) | (15)
Fibrosis | | | 1 (7%) | 1 (7%) | 1 (7%)
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15)
Inflammation, chronic active | 2 (13%) | 2 (13%) | | | 2 (13%)
Alveolar epithelium, hyperplasia, focal | 1 (7%) | | | | 3 (20%)
Special Senses System
None
Urinary System
Kidney | (15) | (15) | (15) | (15) | (15)
Casts protein | 5 (33%) | 4 (27%) | 5 (33%) | 8 (53%) | 7 (47%)
Infiltration cellular, lymphoid | 1 (7%)
Infiltration cellular, lymphocyte | 1 (7%)
Nephropathy | 3 (20%) | | 1 (7%) | 2 (13%) | 1 (7%)

a Number of animals examined microscopically at the site and the number of animals with lesion