# REFERENCES

The Aldrich Library of ^13^C and ^1^H FT-NMR Spectra (1993). 1st ed., p. 1412 (C). Aldrich Chemical Co., Inc., Milwaukee, WI.
The Aldrich Library of FT-IR Spectra (1985). 1st ed. (C.J. Pouchert, Ed.), Vol. 1, p. 876 (A). Aldrich Chemical Co., Inc., Milwaukee, WI.
The Aldrich Library of Infrared Spectra (1981). 3rd ed. (C.J. Pouchert, Ed.), Vol. 1, spectrum 524C (1). Aldrich Chemical Co., Inc., Milwaukee, WI.
Armitage, P. (1971). Statistical Methods in Medical Research, pp. 362–365. John Wiley and Sons, New York.
Ashby, J., and Paton, D. (1993). The influence of chemical structure on the extent and sites of carcinogenesis for 522 rodent carcinogens and 55 different human carcinogen exposures. Mutat. Res. 286, 3–74.7678908
Balu, N., Gamcsik, M.P., Colvin, M.E., Colvin, O.M., Dolan, M.E., and Ludeman, S.M. (2002). Modified guanines representing O^6^-alkylation by the cyclophosphamide metabolites acrolein and chloroacetaldehyde: Synthesis, stability, and ab initio studies. Chem. Res. Toxicol. 15, 380–387.11896686
Bauman, L., and Stenstrom, M.K. (1989). Observations of the reaction between organohalides and sulfite. Environ. Sci. Technol. 23, 232–236.
Beauchamp, R.O., Jr., Andjelkovich, D.A., Kligerman, A.D., Morgan, K.T., and Heck, H.D. (1985). A critical review of the literature on acrolein toxicity. Crit. Rev. Toxicol. 14, 309–380.3902372
Boorman, G.A., Montgomery, C.A., Jr., Eustis, S.L., Wolfe, M.J., McConnell, E.E., and Hardisty, J.F. (1985). Quality assurance in pathology for rodent carcinogenicity studies. In Handbook of Carcinogen Testing (H.A. Milman and E.K. Weisburger, Eds.), pp. 345–357. Noyes Publications, Park Ridge, NJ.
Boorman, G.A., Hickman, R.L., Davis, G.W., Rhodes, L.S., White, N.W., Griffin, T.A., Mayo, J., and Hamm, T.E., Jr. (1986). Serological titers to murine viruses in 90-day and 2-year studies. In Complications of Viral and Mycoplasmal Infections in Rodents to Toxicology Research and Testing (T.E. Hamm, Jr., Ed.), pp. 11–23. Hemisphere Publishing Corporation, Washington, DC.
Cannon, R.E., Spalding, J.W., Trempus, C.S., Szczesniak, C.J., Virgil, K.M., Humble, M.C., and Tennant, R.W. (1997). Kinetics of wound-induced v-Ha-ras transgene expression and papilloma development in transgenic Tg.AC mice. Mol. Carcinog. 20, 108–114.9328441
Code of Federal Regulations (CFR) 21, Part 58.
Cox, D.R. (1972). Regression models and life-tables. J. R. Stat. Soc. B34, 187–220.
Curren, R.D., Yang, L.L., Conklin, P.M., Grafstrom, R.C., and Harris, C.C. (1988). Mutagenesis of xeroderma pigmentosum fibroblasts by acrolein. Mutat. Res. 209, 17–22.3173398
Donehower, L.A., Harvey, M., Slagle, B.L., McArthur, M.J., Montgomery, C.A., Jr., Butel, J.S., and Bradley, A. (1992). Mice deficient for p53 are developmentally normal but susceptible to spontaneous tumours. Nature 356, 215–221.1552940
Dunn, W.J., III, Koehler, M.G., and Emery, S.L. (1987). Application of pattern recognition to mass spectral data of toxic organic compounds in ambient air. Chemom. Intell. Lab. Sys. 1, 321–334.
Dunnett, C.W. (1955). A multiple comparison procedure for comparing several treatments with a control. J. Am. Stat. Assoc. 50, 1096–1121.
Eastin, W.C., Mennear, J.H., Tennant, R.W., Stoll, R.E., Branstetter, D.G., Bucher, J.R., McCullough, B., Binder, R.L., Spalding, J.W., and Mahler, J.F. (2001). Tg.AC genetically altered mouse: Assay working group overview of available data. Toxicol. Pathol. 29 (Suppl.), 60–80.11695563
Eder, E., and Zugelder, J.-P. (1990). DNA-binding studies with allylchloride and allylbromide using the isolated perfused rat liver technique. Toxic. in Vitro 4, 661–665.
Eder, E., Neudecker, T., Lutz, D., and Henschler, D. (1980). Mutagenic potential of allyl and allylic compounds: Structure-activity relationship as determined by alkylating and direct in vitro mutagenic properties. Biochem. Pharmacol. 29, 993–998.6992786
Eder, E., Henschler, D., and Neudecker, T. (1982). Mutagenic properties of allylic and α,β-unsaturated compounds: Consideration of alkylating mechanisms. Xenobiotica 12, 831–848.6763406
Eder, E., Schiffmann, D., Neudecker, T., and Henschler, D. (1983). Dependence of direct genotoxic activities of allylic compounds on their alkylating properties. J. Cancer Res. Clin. Oncol. 105, A17.
Eder, E., Schiffmann, D., Dornbusch, K., Kütt, W., and Hoffman, C. (1986). Genotoxicity of allyl compounds – a quick screening strategy based on structure-activity relationships and a battery of prescreening tests. Food Chem. Toxicol. 24, 667–673.3781422
Eder, E., Lutz, D., and Jörns, M. (1987). Allylic compounds bind directly to DNA: Investigation of the binding mechanisms in vitro. Chem. Biol. Interact. 61, 97–108.3030573
Eder, E., Hoffman, C., Sporer, S., and Scheckenbach, S. (1993). Biomonitoring studies and susceptibility markers for acrolein congeners and allylic and benzyl com pounds. Environ. Health Perspect. 99, 245–247.8319634
Foiles, P.G., Akerkar, S.A., Migleitta, L.M., and Chung, F.L. (1990). Formation of cyclic deoxyguanosine adducts in Chinese hamster ovary cells by acrolein and crotonaldehyde. Carcinogenesis 11, 2059–2061.2225341
Foureman, P., Mason, J.M., Valencia, R., and Zimmering, S. (1994). Chemical mutagenesis testing in Drosophila. X. Results of 70 coded chemicals tested for the National Toxicology Program. Environ. Mol. Mutagen. 23, 208–227.8162896
Galloway, S.M., Armstrong, M.J., Reuben, C., Colman, S., Brown, B., Cannon, C., Bloom, A.D., Nakamura, F., Ahmed, M., Duk, S., Rimpo, J., Margolin, B.H., Resnick, M.A., Anderson, B., and Zeiger, E. (1987). Chromosome aberrations and sister chromatid exchanges in Chinese hamster ovary cells: Evaluations of 108 chemicals. Environ. Mol. Mutagen. 10 (Suppl. 10), 1–175.3319609
Gart, J.J., Chu, K.C., and Tarone, R.E. (1979). Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. JNCI 62, 957–974.285297
Gosselin, R.E., Smith, R.P., Hodge, H.C., and Braddock, J. (1984). Clinical Toxicology of Commercial Products, 5th ed., p. II–204. Williams and Wilkins, Baltimore.
Grassie, N., Diab, M.A.M., and Scotney, A. (1986). Thermal degradation of bromine-containing polymers. Part 7. Poly (2,3-dibromopropyl methacrylate) and poly (2,3-dibromopropyl acrylate). Polym. Degrad. Stab. 16, 79–97.
Gulati, D.K., Witt, K., Anderson, B., Zeiger, E., and Shelby, M.D. (1989). Chromosome aberration and sister chromatid exchange tests in Chinese hamster ovary cells in vitro. III. Results with 27 chemicals. Environ. Mol. Mutagen. 13, 133–193.2917552
Hales, B.F. (1982). Comparison of the mutagenicity and the teratogenicity of cyclophosphamide and its active metabolites, 4-hydroxycyclophosphamide, phosphor-amide mustard, and acrolein. Cancer Res. 42, 3016–3021.7046914
Hansch, C., Leo, A., and Hoekman, D. (1995). Exploring QSAR. Hydrophobic, Electronic, and Steric Constants. ACS Professional Reference Book, American Chemical Society, Washington, DC.
Harris, C.C. (1996a). Structure and function of the p53 tumor suppresor gene: Clues for rational cancer therapeutic strategies. J. Natl. Cancer Inst. 88, 1442–1455.8841019
Harris, C.C. (1996b). p53 tumor suppressor gene: From the basic research laboraory to the clinic — an abridged historical perspective. Carcinogenesis 17, 1187–1198.8681432
Harris, C.C. (1996c). The 1995 Walter Hubert Lecture - molecular epidemiology of human cancer: Insights from the mutational analysis of the p53 tumour-suppressor gene. Brit. J. Cancer 73, 261–269.8562328
Haworth, S., Lawlor, T., Mortelmans, K., Speck, W., and Zeiger, E. (1983). Salmonella mutagenicity test results for 250 chemicals. Environ. Mutagen. 5 (Suppl. 1), 3–142.
Hazardous Substances Data Bank (HSDB) (2003). National Institute for Occupational Safety and Health, HSDB database available through the National Library of Medicine TOXNET System.
Henschler, D., and Eder, E. (1986). Structure-activity relationships of alpha, beta-unsaturated carbonylic compounds. IARC Sci. Publ. 70, 197–205.
Hollander, M., and Wolfe, D.A. (1973). Nonparametric Statistical Methods, pp. 120–123. John Wiley and Sons, New York.
Honchel, R., Rosenzweig, B.A., Thompson, K.L., Blanchard, K.T., Furst, S.M., Stoll, R.E., and Sistare, F.D. (2001). Loss of palindromic symmetry in Tg.AC mice with a nonresponder phenotype. Mol. Carcinog. 30, 99–110.11241757
Integrated Laboratory Systems (ILS) (1990). Micronucleus Data Management and Statistical Analysis Software, Version 1.4. ILS, Inc., P.O. Box 13501, Research Triangle Park, NC 27707.
Kaplan, E.L., and Meier, P. (1958). Nonparametric estimation from incomplete observations. J. Am. Stat. Assoc. 53, 457–481.
Kaye, C.M., Clapp, J.J., and Young, L. (1972). The metabolic formation of mercapturic acids from allyl halides. Xenobiotica 2, 129–139.5056811
Kim, J.N., Kim, K.M., and Ryu, E.K. (1992). Improved synthesis of N-alkoxyphthalimides. Synth. Commun. 22, 1427–1432.
Kirino, O., Oshita, H., Oishi, T., and Kato, T. (1980). Preventative activities of N-substituted-α-aminonitriles against Fusarium diseases. Agric. Biol. Chem. 44, 25–30.
Krause, R.J., Glocke, S.C., and Elfarra, A.A. (2002). Sulfoxides as urinary metabolites of S-allyl-l-cysteine in rats: Evidence for the involvement of flavin-containing monooxygenases. Drug Metab. Dispos. 30, 1137–1142.12228191
Leder, A., Kuo, A., Cardiff, R.D., Sinn, E., and Leder, P. (1990). v-Ha-ras transgenic abrogates the initiation step in mouse skin tumorigenesis: Effects of phorbol esters and retinoic acid. Proc. Natl. Acad. Sci. 87, 9178–9182.2251261
Lewis, R.J. (1996). Sax’s Dangerous Properties of Industrial Materials, 9th ed., Vols. 1–3, p. 94. Van Nostrand Reinhold, New York.
Lewis, R.J. (1997). Hazardous Chemicals Desk Reference, 4th ed. Van Nostrand Reinhold, New York.
Lijinsky, W. (1988). Chronic studies in rodents of vinyl acetate and compounds related to acrolein. Ann. N.Y. Acad. Sci. 534, 246–254.3389658
Lijinsky, W., and Andrews, A.W. (1980). Mutagenicity of vinyl compounds in Salmonella typhimurium. Teratog. Carcinog. Mutagen. 1, 259–267.6119816
Lijinsky, W., and Reuber, M.D. (1987). Chronic carcinogenesis studies of acrolein and related compounds. Toxicol. Ind. Health 3, 337–345.3686537
Lipnick, R.L., Watson, K.R., and Strausz, A.K. (1987). A QSAR study of the acute toxicity of some industrial organic chemicals to goldfish. Narcosis, electrophile and proelectrophile mechanisms. Xenobiotica 17, 1011–1025.3673107
Lutz, D., Eder, E., Neudecker, T., and Henschler, D. (1982). Structure-mutagenicity relationship in α,β-unsaturated carbonylic compounds and their corresponding allylic alcohols. Mutat. Res. 93, 305–315.
MacGregor, J.T., Wehr, C.M., Henika, P.R., and Shelby, M.D. (1990). The in vivo erythrocyte micronucleus test: Measurement at a steady state increases assay efficiency and permits integration with toxicity studies. Fundam. Appl. Toxicol. 14, 513–522.2111256
Mahler, J.F., Stokes, W., Mann, P.C., Takaoka, M., and Maronpot, R.R. (1996). Spontaneous lesions in aging FVB/N mice. Toxicol. Pathol. 24, 710–716.8994298
Mahler, J.F., Flagler, N.D., Malarkey, D.E., Mann, P.C., Haseman, J.K., and Eastin, W. (1998). Spontaneous and chemically induced proliferative lesions in Tg.AC transgenic and p53-heterozygous mice. Toxicol. Pathol. 26, 501–511.9715509
Marnett, L.J., Hurd, H.K., Holstein, M.C., Levin, D.E., Esterbauer, H., and Ames, B.N. (1985). Naturally occurring carbonyl compounds are mutagens in Salmonella tester strain TA104. Mutat. Res. 148, 25–34.3881660
Maronpot, R.R., and Boorman, G.A. (1982). Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol. Pathol. 10, 71–80.28094716
The Merck Index (1996). 12th ed. (S. Budavari, Ed.), p. 53. Merck and Company Inc., Whitehouse Station, NJ.
Milano, J.C., and Vernet, J.L. (1988). Degradation par photolyse du dibromo-1,2-propane present a l’etat de traces dans l’eau - influence du peroxyde d’hydrogene. Chemosphere 17, 963–971.
Myhr, B.C., and Caspary, W.J. (1991). Chemical mutagenesis at the thymidine kinase locus in L5178Y mouse lymphoma cells: Results for 31 coded compounds in the National Toxicology Program. Environ. Mol. Mutagen. 18, 51–83.1864269
National Cancer Institute (NCI) (1977). Bioassay of Allyl Chloride for Possible Carcinogenicity (CAS No. 107-05-01). Technical Report Series No. 73. NIH Publication No. 78-1323. U.S. Department of Health, Education, and Welfare, Public Health Service, National Institutes of Health, Bethesda, MD.
National Fire Protection Association (NFPA) (1997). Fire Protection Guide on Hazardous Materials, 12th ed. NFPA, Quincy, MA.
National Toxicology Program (NTP) (2006). Comparative Toxicity Studies of Allyl Acetate, Allyl Alcohol, and Acrolein (CAS Nos. 591-87-7, 107-18-6, and 107-02-8) Administered by Gavage to F344/N Rats and B6C3F_1_ Mice. Toxicity Report Series No. 48. NIH Publication No. 06-4413. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
Parent, R.A., Caravello, H.E., and Long, J.E. (1991). Oncogenicity study of acrolein in mice. J. Am. Coll. Toxicol. 10, 647–659.
Parent, R.A., Caravello, H.E., and Long, J.E. (1992). Two-year toxicity and carcinogenicity study of acrolein in rats. J. Appl. Toxicol. 12, 131–139.1556380
Parent, R.A., Caravello, H.E., and San, R.H. (1996). Mutagenic activity of acrolein in S. typhimurium and E. coli. J. Appl. Toxicol. 16, 103–108.8935782
Pritchard, J.B., French, J.E., Davis, B.J., and Haseman, J.K. (2003). The role of transgenic mouse models in carcinogen identification. Environ. Health Perspect. 111, 444–454.12676597
Rao, G.N., Haseman, J.K., and Edmondson, J. (1989a). Influence of viral infections on body weight, survival, and tumor prevalence in Fischer 344/NCr rats on two-year studies. Lab. Anim. Sci. 39, 389–393.2554057
Rao, G.N., Piegorsch, W.W., Crawford, D.D., Edmondson, J., and Haseman, J.K. (1989b). Influence of viral infections on body weight, survival, and tumor prevalence of B6C3F_1_ (C57BL/6N × C3H/HeN) mice in carcinogenicity studies. Fundam. Appl. Toxicol. 13, 156–164.2767355
Registry of Toxic Effects of Chemical Substances (RTECS) [database online] (2002): National Institute for Occupational Safety and Health; 1971 to present. Updated quarterly. Available from the National Library of Medicine, Bethesda, MD.
Schiffmann, D., Eder, E., Neudecker, T., and Henschler, D. (1983). Induction of unscheduled DNA synthesis in HeLa cells by allylic compounds. Cancer Lett. 20, 263–269.
Schuphan, I., and Casida, J.E. (1979a). [2,3]Sigmatrophic rearrangement of S-(3-chloroallyl) thiocarbamate sulfoxides followed by a 1,2-elimination reaction yielding unsaturated aldehydes and acid chlorides. Tetrahedron Lett. 10, 841–844.
Schuphan, I., and Casida, J.E. (1979b). S-chloroallyl thiocarbamate herbicides: Chemical and biological formation and rearrangement of diallate and triallate sulfoxides. J. Agric. Food. Chem. 27, 1060–1067.
Shafer, D. (1995). The Book of Chemical Lists, Vol. II, pp. 15–18. Business and Legal Reports, Inc., Madison, CT.
Shelby, M.D., Erexson, G.L., Hook, G.J., and Tice, R.R. (1993). Evaluation of a three-exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ. Mol. Mutagen. 21, 160–179.8444144
Sottani, C., Tranfo, G., Faranda, P., and Minoia, C. (2005). Highly sensitive high-performance liquid chromatography/selective reaction monitoring mass spectrometry method for the determination of cyclophosphamide and ifosfamide in urine of health care workers exposed to antineoplastic agents. Rapid Commun. Mass Spectrom. 19, 2794–2800.16144038
Spalding, J.W., Momma, J., Elwell, M.R., and Tennant, R.W. (1993). Chemically induced skin carcinogenesis in a transgenic mouse line (TG•AC) carrying a v-Ha-ras gene. Carcinogenesis 14, 1335–1341.8330346
Spalding, J.W., French, J.E., Tice, R.R., Furedi-Machacek, M., Haseman, J.K., and Tennant, R.W. (1999). Development of a transgenic mouse model for carcinogenesis bioassays: Evaluation of chemically induced skin tumors in Tg.AC mice. Toxicol. Sci. 49, 241–254.10416269
Stenger, V.A. (1978). Bromine compounds. In Kirk-Othmer Encylopedia of Chemical Technology, 3rd ed. (M. Grayson, Ed.), Vol. 4, pp. 256–259. John Wiley and Sons, New York.
STN (1994). The Scientific and Technical Information Network, STN International, databases searched.
Tarone, R.E. (1975). Tests for trend in life table analysis. Biometrika 62, 679–682.
Tennant, R.W., French, J.E., and Spalding, J.W. (1995). Identifying chemical carcinogens and assessing potential risk in short-term bioassays using transgenic mouse models. Environ. Health Perspect. 103, 942–950.8529591
Tennant, R.W., Spalding, J.W., and French, J.E. (1996). Evaluation of transgenic mouse bioassays for identifying carcinogens and noncarcinogens. Mutat. Res. 365, 119–127.8898993
Tennant, R.W., Stasiewicz, S., Mennear, J., French, J.E., and Spalding, J.W. (1999). Genetically altered mouse models for identifying carcinogens. IARC Sci. Publ. 146, 123–150.
Tennant, R.W., Stasiewicz, S., Eastin, W.C., Mennear, J.H., and Spalding, J.W. (2001). The Tg.AC (v-Ha-ras) transgenic mouse: Nature of the model. Toxicol. Pathol. 29, 51–59.11695562
Thompson, K.L., Rosenzweig, B.A., and Sistare, F.D. (1998). An evaluation of the hemizygous transgenic Tg.AC mouse for carcinogenicity testing of pharmaceuticals. II. A genotypic marker that predicts tumorigenic responsiveness. Toxicol. Pathol. 26, 548–555.9715514
Thompson, K.L., Rosenzweig, B.A., Honchel, R., Cannon, R.E., Blanchard, K.T., Stoll, R.E., and Sistare, F.D. (2001). Loss of critical palindromic transgene promoter sequence in chemically induced Tg.AC mouse skin papillomas expressing transgene-derived mRNA. Mol. Carcinog. 32, 176–186.11746829
Trempus, C.S., Mahler, J.F., Ananthaswamy, H.N., Loughlin, S.M., French, J.E., and Tennant, R.W. (1998). Photocarcinogenesis and susceptibility to UV radiation in the v-Ha-ras transgenic Tg.AC mouse. J. Invest. Dermatol. 111, 445–451.9740239
United States Environmental Protection Agency (USEPA) (2002). Inventory Update Rule 2002. Allyl Bromide, CAS No. 106956. U.S. Environmental Protection Agency, Office of Research and Development, National Center for Environmental Assessment, Washington Office, Washington, DC. <http://www.epa.gov/oppt/iur/iur02/search03.htm>.
U.S. Environmental Protection Agency (USEPA) (2006). Toxic Substances Control Act Chemical Substance Inventory. Office of Toxic Substances. Washington, DC.
van der Avoort, I.A.M., Shirango, H., Hoevenaars, B.M., Grefte, J.M.M., de Hullu, J.A., de Wilde, P.C.M., Bulten, J., Melchers, W.J.G., and Massuger, L.F.A.G. (2005). Vulvar squamous cell carcinoma is a multifactorial disease following two separate and independent pathways. Int. J. Gynecol. Pathol. 25, 22–29.
Williams, D.A. (1971). A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics 27, 103–117.5547548
Williams, D.A. (1972). The comparison of several dose levels with a zero dose control. Biometrics 28, 519–531.5037867
Witt, K.L., Knapton, A., Wehr, C.M., Hook, G.J., Mirsalis, J., Shelby, M.D., and MacGregor, J.T. (2000). Micronucleated erythrocyte frequency in peripheral blood of B6C3F_1_ mice from short-term, prechronic, and chronic studies of the NTP Carcinogenesis Bioassay Program. Environ. Mol. Mutagen. 36, 163–194.11044899
Wright, J.T., Hansen, L., Mahler, J., Szczesniak, C., and Spalding, J.W. (1995). Odontogenic tumours in the v-Ha-ras (TG·AC) transgenic mouse. Arch. Oral Biol. 40, 631–638.7575235
Yalkowsky, S.H., and Dannenfelser, R.M. (1992). The AQUASOL DATABASE of aqueous solubility, Version 5. College of Pharmacy, University of Arizona, Tucson, AZ.
Zeiger, E., Anderson, B., Haworth, S., Lawlor, T., and Mortelmans, K. (1988). Salmonella mutagenicity tests. IV. Results from the testing of 300 chemicals. Environ. Mol. Mutagen. 11 (Suppl. 12), 1–158.
Zeiger, E., Anderson, B., Haworth, S., Lawlor, T., and Mortelmans, K. (1992). Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ. Mol. Mutagen. 19 (Suppl. 21), 2–141.1541260
Zenkevich, I., and Konyukhova, S.V. (1992). Gas chromatographic identification of ecologically safe freons. Fiz. Khim. 1, 66–70.