# SUMMARY OF TECHNICAL REPORTS REVIEW SUBCOMMITTEE COMMENTS

On August 28, 2006, the draft Report on the toxicology and carcinogenesis studies of allyl bromide received public review by the National Toxicology Program’s Board of Scientific Counselors’ Technical Reports Review Subcommittee. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. J.E. French, NIEHS, provided an overview of the development of the genetically modified mouse models used in the studies being reported. Dr. J.K. Dunnick, NIEHS, introduced the studies of allyl bromide in p53 haploinsufficient and Tg.AC hemizygous mice by describing the uses of the chemical, the study rationale, the details of the study design and dose selection, and the results of the histopathologic examination of the animals. The proposed conclusions were: no evidence of carcinogenic activity in male or female p53 haploinsufficient mice administered allyl bromide at 0.5, 1, 2, 4, or 8 mg/kg per day by corn oil gavage, 5 days a week for 40 weeks. There was a marginal increase in the incidence of squamous cell papillomas, primarily of the vulva, in female Tg.AC hemizygous mice administered allyl bromide by corn oil gavage for 40 weeks.

Dr. Giesy, the first principal reviewer, did not have any scientific criticisms, felt the report presented the results clearly, and agreed with the proposed conclusions.

Dr. Mirsalis, the second principal reviewer, questioned the decision to perform a gavage study in the FVB/N mice at doses that showed no effect in a pilot dermal study. He suggested more explanation of the rationale for design of that study. He felt the other studies were valid and agreed with the proposed conclusions.

Dr. Sikka, the third principal reviewer, suggested additions to the metabolic pathway diagram and asked for an explanation of why the chemical was mutagenic in the absence, but not the presence, of metabolic activation.

Dr. Dunnick replied that the discussions of mutagenicity and the descriptions of study design would be amplified. She noted that oral gavage was the route of choice for all the genetically modified mouse model studies.

Dr. Mirsalis moved, and Dr. Giesy seconded, that the conclusions be accepted as written. The motion was approved unanimously with seven votes.