# DISCUSSION AND CONCLUSIONS

These studies were performed to determine the toxicity and carcinogenicity of allyl bromide in Tg.AC hemizygous and p53 haploinsufficient mice. No conventional 2-year bioassays have been conducted on allyl bromide.

The 2-week studies were conducted in the parent strains of the Tg.AC hemizygous and p53 haploinsufficient mice, which were FVB/N and C57BL/6 mice, respectively. In the 2-week dermal studies in FVB/N mice, there were no treatment-related histopathologic changes or treatment-related effects on body weight or mortality. The volatility of allyl bromide may have resulted in limited exposure by dermal administration.

In the 2-week gavage study conducted in C57BL/6 mice, there were biologically significant increases in the incidences of forestomach lesions at 15, 30, 60, and 120 mg/kg. In 14-week gavage studies on the allyl bromide metabolites allyl alcohol and acrolein, the forestomach was also the target organ for toxicity in F344/N rats and B6C3F_1_ mice (NTP, 2006). Allyl alcohol caused forestomach hyperplasia in mice (but not in rats) at 12, 25, and 50 mg/kg. Acrolein caused forestomach hyperplasia in rats at 10 mg/kg and forestomach or glandular stomach toxicity and/or necrosis in mice at 5, 10, and 20 mg/kg. Thus, the forestomach was a target organ for toxicity after administration of allyl bromide or its metabolites, allyl alcohol or acrolein.

Because of the lack of toxicity via the dermal route of exposure in the 2-week allyl bromide study, the gavage route of administration was chosen for the 40-week studies in male and female FVB/N mice, Tg.AC hemizygous mice, C57BL/6 mice, and p53 haploinsufficient mice using a high dose of 8 mg/kg.

Activation of the ras gene in Tg.AC mice is under the control of the zeta-globin promoter. The v-Ha-ras structural gene has a terminal simian virus 40 polyadenylation signal (Thompson et al., 1998). In some previous studies with Tg.AC mice, a nonresponsive phenotype was identified, and 12-O-tetradecanoylphorbol-13-acetate (TPA) failed to induce skin papillomas (Thompson et al., 1998, 2001). Therefore, TPA is included as a positive control in Tg.AC mouse studies to test whether the mice have the full spectrum of genetic components of the v-Ha-ras gene for skin tumor induction. In this Tg.AC allyl bromide study, TPA did induce skin papillomas, and the Tg.AC mice used were considered to contain the necessary promoters and v-Ha-ras gene components.

In the 40-week study conducted in Tg.AC mice, the increase in total skin papillomas and vulvar tumors in female mice was significant by the Cochran-Armitage trend statistic. One hypothesis for this effect is the formation of a reactive metabolite derived from allyl mercapturic acid sulfoxide that was excreted in the urine, was absorbed by surrounding tissue (such as vulvar cells), and caused DNA damage (Kaye et al., 1972; Schuphan and Casida, 1979a,b). There were no treatment-related lesions in the forestomach.

In humans, there are two pathways leading to vulvar tumors: one pathway is associated with exposure to human papilloma virus (HPV), the other is an HPV-independent pathway (van der Avoort et al., 2005). The hypothesis that an HPV-independent pathway may lead to vulvar tumors is supported by the current study and by treatment-related vulvar squamous cell papillomas seen in a cyclophosphamide gavage study conducted in Tg.AC mice (Eastin et al., 2001). Cyclophosphamide and metabolites are excreted in urine, which may expose vulva cells to carcinogens (Sottani et al., 2005). Allyl bromide and cyclophosphamide (Balu et al., 2002) are both metabolized to acrolein and likely have other metabolites in common. It remains to be demonstrated if the common metabolites are responsible for the common response.

There were no significant allyl bromide treatment-related increases in tumors in the other mice studied (FVB/N, C57BL/6, and p53 haploinsufficient mice). Studies of the allyl bromide metabolite acrolein also showed no evidence for a carcinogenic effect in rats or mice. A study on the potential of acrolein to cause cancer in CD-1 mice receiving 0, 0.5, 2, or 4.5 mg/kg per day by gavage for 18 months showed no evidence, nor did an acrolein study in Sprague-Dawley rats receiving 0, 0.05, 0.5, or 2.5 mg/kg per day by gavage for 18 months (Parent et al., 1991, 1992). No acrolein-induced cancers were seen when the chemical was administered in the drinking water to F344/N rats for up to 2 years (Linjinsky and Reuber, 1987; Linjinsky, 1988).

In NTP studies, allyl bromide was mutagenic in S. typhimurium strain TA100, with and without liver activation enzymes. The frequencies of micronucleated erythrocytes were determined at terminal sacrifice in the transgenic strains and their corresponding parent strains; no treatment-related increases in micronucleated erythrocytes were observed in male or female mice in any of the four strains. The erythrocyte micronucleus assay detects numerical or structural chromosomal damage induced in nucleated precursor cells in the bone marrow. Allyl bromide, a direct alkylating agent, may bind to proteins in blood, which might prevent the chemical or mutagenic metabolites from reaching the bone marrow. Alternatively, allyl bromide may induce point mutations exclusively.

## Conclusions

Under the conditions of this study, there was no evidence of carcinogenic activity^*^ in male or female p53 haplo-insufficient mice administered allyl bromide at 0.5, 1, 2, 4, or 8 mg/kg per day by corn oil gavage, 5 days a week for 40 weeks.

There was a marginal increase in the incidence of squamous cell papillomas, primarily of the vulva, in female Tg.AC hemizygous mice administered allyl bromide by corn oil gavage for 40 weeks. No treatment-related neoplasms were seen in male Tg.AC hemizygous mice administered allyl bromide by gavage at 0.5, 1, 2, 4, or 8 mg/kg, 5 days per week for 40 weeks.

* Explanation of Levels of Evidence of Carcinogenic Activity is on page 9. A summary of the Technical Reports Review Subcommittee comments and the public discussion on this Report appears on page 11.