# RESULTS

## 2-Week Dermal Study in FVB/n Mice

All animals survived to the end of the study (Table 2). Final group mean body weights and body weight gains of dosed males and females were similar to those of the vehicle control groups (Table 2). No chemical-related clinical findings were observed.

There were no significant differences in organ weights in male or female mice treated with allyl bromide when compared to their respective vehicle controls (Table F1). No chemical-related gross observations were noted at necropsy. Under microscopic observation, one female in the group administered 120 mg/kg had a hyperplasia of the skin at the site of application.

TABLE 2 Survival and Body Weights of FVB/N Mice in the 2-Week Dermal Study of Allyl Bromide

Dose (mg/kg) | Survival^a^ | Mean Body Weight^b^ (g) | | | Final Weight Relative to Controls (%)
Dose (mg/kg) | Survival^a^ | Initial | Final | Change | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 24.7 ± 0.8 | 27.1 ± 0.9 | 2.4 ± 0.6
7.5 | 5/5 | 24.6 ± 0.8 | 27.2 ± 0.9 | 2.5 ± 0.3 | 100
15 | 5/5 | 24.6 ± 0.4 | 27.0 ± 0.2 | 2.4 ± 0.3 | 100
30 | 5/5 | 25.4 ± 0.6 | 27.2 ± 0.4 | 1.8 ± 0.4 | 100
60 | 5/5 | 24.0 ± 1.0 | 27.6 ± 0.5 | 3.6 ± 1.4 | 102
120 | 5/5 | 25.1 ± 0.4 | 27.5 ± 0.9 | 2.4 ± 0.9 | 101
Female
0 | 5/5 | 19.6 ± 0.6 | 21.5 ± 0.5 | 2.0 ± 0.2
7.5 | 5/5 | 19.1 ± 0.5 | 21.9 ± 0.5 | 2.8 ± 0.3 | 102
15 | 5/5 | 19.3 ± 0.2 | 20.9 ± 0.4 | 1.6 ± 0.2 | 97
30 | 5/5 | 19.2 ± 0.4 | 21.3 ± 0.4 | 2.1 ± 0.5 | 99
60 | 5/5 | 19.8 ± 0.6 | 21.8 ± 0.3 | 2.0 ± 0.4 | 101
120 | 5/5 | 19.5 ± 0.7 | 21.8 ± 0.5 | 2.3 ± 0.3 | 101

a Number of animals surviving at 17 days/number initially in group

b Weights and weight changes are given as mean ± standard error. Differences from the vehicle control groups are not significant by Dunnett’s test.

## 2-Week Gavage Study in C57BL/6 Mice

Three 120 mg/kg male mice died prior to the terminal sacrifice (Table 3). All female mice survived to the end of the study. Final mean body weights and body weight gains of dosed mice were similar to those of the vehicle control groups (Table 3). Lethargy was observed in one male each in the 60 and 120 mg/kg groups and in two females in the 120 mg/kg group.

Absolute and relative liver weights of 30 and 60 mg/kg males were significantly greater than those of the vehicle control group (Table F4). Absolute and relative testis weights of 60 mg/kg males and absolute and relative heart weights of 120 mg/kg females were significantly less.

Dosed mice developed nonneoplastic lesions in the forestomach (Table 4). Treatment caused severe, necrotizing, and ulcerative gastritis, occasionally with transmural ulcers, in male and female mice, particularly at high doses. At necropsy, adhesions of the stomach serosa to surrounding organs (liver and spleen) and abdominal wall were evident in 40% to 100% of the mice in the 60 and 120 mg/kg groups (data not shown). These findings are consistent with peritonitis associated with degeneration, necrosis, and ulceration observed in all dosed groups leading to transmural, gastric ulcers in some mice in the 120 mg/kg groups. There were also treatment-related increases in the incidences of gastric epithelial hyperplasia and inflammation.

TABLE 3 Survival and Body Weights of C57BL/6 Mice in the 2-Week Gavage Study of Allyl Bromide

Dose (mg/kg) | Survival^a^ | Mean Body Weight^b^ (g) | | | Final Weight Relative to Controls (%)
Dose (mg/kg) | Survival^a^ | Initial | Final | Change | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 21.0 ± 1.3 | 22.2 ± 0.9 | 1.2 ± 1.2
7.5 | 5/5 | 21.4 ± 0.9 | 23.1 ± 0.6 | 1.7 ± 0.9 | 104
15 | 5/5 | 21.8 ± 0.8 | 23.2 ± 1.0 | 1.4 ± 0.4 | 104
30 | 5/5 | 22.2 ± 0.5 | 23.5 ± 0.9 | 1.3 ± 0.5 | 106
60 | 5/5 | 21.7 ± 0.9 | 23.1 ± 0.8 | 1.4 ± 0.3 | 104
120 | 2/5^c^ | 21.1 ± 1.4 | 22.2 ± 0.4 | 0.0 ± 0.0 | 100
Female
0 | 5/5 | 17.1 ± 0.3 | 19.8 ± 0.5 | 2.7 ± 0.6
7.5 | 5/5 | 17.7 ± 0.6 | 19.2 ± 1.1 | 1.5 ± 1.0 | 97
15 | 5/5 | 17.3 ± 0.5 | 20.0 ± 0.5 | 2.8 ± 0.4 | 101
30 | 5/5 | 17.5 ± 0.3 | 19.7 ± 0.7 | 2.3 ± 0.8 | 99
60 | 5/5 | 17.3 ± 0.5 | 18.7 ± 0.5 | 1.4 ± 0.6 | 94
120 | 5/5 | 17.1 ± 0.5 | 18.6 ± 0.8 | 1.5 ± 0.3 | 94

a Number of animals surviving at 17 days/number initially in group

b Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study. Differences from the control group are not significant by Dunnett’s test.

c Days of death: 7, 8, 13

TABLE 4 Nonneoplastic Forestomach Lesions in C57BL/6 Mice in the 2-Week Gavage Study of Allyl Bromide

| Vehicle ontrol | 7.5 mg/kg | 15 mg/kg | 30 mg/kg | 60 mg/kg | 120 mg/kg
Male
Number Examined Microscopically | 5 | 5 | 5 | 5 | 5 | 5
Hyperkeratosis, Diffuse^a^ | 0 | 0 | 1 | 2 | 2 | 2
Hyperkeratosis, Focal | 0 | 0 | 2 | 1 | 3 | 1
Epithelium, Degeneration, Diffuse | 0 | 1 | 1 | 1 | 1 | 0
Epithelium, Degeneration, Focal | 0 | 0 | 2 | 2 | 0 | 0
Epithelium, Hyperplasia, Diffuse | 0 | 0 | 1 | 2 | 0 | 1
Epithelium, Hyperplasia, Focal | 0 | 0 | 2 | 1 | 4^*^ | 2
Epithelium, Inflammation, Chronic Active, Focal | 0 | 0 | 1 | 3 | 1 | 0
Epithelium, Ulcer, Focal | 0 | 0 | 0 | 0 | 0 | 1
Female
Number Examined Microscopically | 5 | 5 | 5 | 5 | 5 | 5
Hyperkeratosis, Diffuse | 0 | 2 | 0 | 2 | 0 | 1
Hyperkeratosis, Focal | 0 | 0 | 0 | 0 | 5^**^ | 4^*^
Epithelium, Degeneration, Focal | 0 | 1 | 4^*^ | 5^**^ | 0 | 0
Epithelium, Hyperplasia, Focal | 0 | 3 | 4^*^ | 5^**^ | 5^**^ | 5^**^
Epithelium, Inflammation, Chronic Active, Focal | 0 | 0 | 0 | 2 | 0 | 0
Epithelium, Necrosis, Focal | 0 | 0 | 0 | 0 | 2 | 0
Muscularis, Serosa, Epithelium, Inflammation, Chronic Active, Focal | 0 | 0 | 0 | 0 | 4^*^ | 0
Muscularis, Serosa, Epithelium, Ulcer, Focal | 0 | 0 | 0 | 0 | 3 | 5^**^

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test

** P≤0.01

a Number of animals with lesion

Dose Selection Rationale: In the 2-week C57BL/6 mouse study, there were significant forestomach lesions at the 15, 30, 60, and 120 mg/kg concentrations. Because of this forestomach toxicity, a high dose of 8 mg/kg per day was selected for the 40-week study in p53 haploinsufficient mice. No toxicity was seen in the FVB/N mice in the 2-week dermal study. Thus, in the 40-week study in Tg.AC hemizygous mice, the oral route of administration was used at the same doses as in the 40-week study in p53 haploinsufficient mice. The parental strains (FVB/N and C57BL/6 mice) were exposed to 0 or 8 mg/kg by corn oil gavage in 40-week studies. In the allyl bromide studies in the p53 and Tg.AC mice, there was no evidence for tumor formation or decrease in survival at 26 weeks. Exposure was continued to 40 weeks to allow more time for the development of toxic or carcinogenic processes.

## 40-Week Gavage Study in FVB/n Mice

### Survival

Estimates of 40-week survival probabilities for male and female mice are shown in Table 5. Survival of dosed male and female mice was similar to that of the vehicle control groups. One male and one female administered 8 mg/kg died before the end of the study.

### Body Weights, Clinical Findings, and Organ Weights

Mean body weights of dosed male mice were generally similar to those of vehicle controls, and those of dosed female mice were generally greater throughout the study (Figure 2; Tables 6 and 7). There were no treatment-related clinical findings. Organ weights of 8 mg/kg males and females were similar to those of the vehicle control groups (Table F2).

### Pathology and Statistical Analyses

There were no statistically or biologically significant increases in neoplasms or nonneoplastic lesions in FVB/N mice administered allyl bromide by gavage for 40 weeks. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Appendix A for male and female FVB/N mice. Three (20%) dosed males (8 mg/kg), two (13%) vehicle control females, and one (7%) dosed female (8 mg/kg) developed alveolar/bronchiolar adenomas (Tables A1 and A2). Mahler et al. (1996) reported spontaneous alveolar/bronchiolar adenoma rates in 14-month-old FVB/N mice of 2/45 (4%) for males and 8/98 (8%) for females. Mice in the current study were approximately 11 months old at the end of the study.

TABLE 5 Survival of FVB/N Mice in the 40-Week Gavage Study of Allyl Bromide

| Vehicle Control | 8 mg/kg
Male
Animals initially in study | 15 | 15
Accidental death^a^ | 0 | 1
Animals surviving to study termination | 15 | 14
Percent probability of survival at end of study^b^ | 100 | 100
Mean survival (days)^c^ | 277 | 259
Survival analysis^d^ | | —^e^
Female
Animals initially in study | 15 | 15
Moribund | 0 | 1
Animals surviving to study termination | 15 | 14
Percent probability of survival at end of study | 100 | 93
Mean survival (days) | 276 | 272
Survival analysis | | P=1.000

a Censored from survival analysis

b Kaplan-Meier determinations

c Mean of all deaths (uncensored, censored, and terminal sacrifice)

d The results of the life table pairwise comparisons (Cox, 1972) with the vehicle controls are in the dosed group column.

e Value of statistic cannot be computed.

FIGURE 2 Growth Curves for Male and Female FVB/N Mice Exposed to Allyl Bromide by Gavage for 40 Weeks

TABLE 6 Mean Body Weights and Survival of Male FVB/N Mice in the 40-Week Gavage Study of Allyl Bromide

Weeks on Study | Vehicle Control | | 8 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 25.8 | 15 | 25.5 | 99 | 15
2 | 26.3 | 15 | 26.6 | 101 | 14
3 | 25.6 | 15 | 27.7 | 108 | 14
4 | 27.3 | 15 | 28.4 | 104 | 14
5 | 29.1 | 15 | 29.3 | 101 | 14
6 | 30.1 | 15 | 30.1 | 100 | 14
7 | 30.4 | 15 | 30.2 | 99 | 14
8 | 30.3 | 15 | 30.4 | 100 | 14
9 | 30.9 | 15 | 31.3 | 101 | 14
10 | 31.6 | 15 | 31.6 | 100 | 14
11 | 32.1 | 15 | 32.7 | 102 | 14
12 | 32.3 | 15 | 33.2 | 103 | 14
13 | 32.1 | 15 | 32.1 | 100 | 14
14 | 33.8 | 15 | 33.7 | 100 | 14
15 | 34.0 | 15 | 34.7 | 102 | 14
16 | 35.3 | 15 | 35.1 | 99 | 14
17 | 35.4 | 15 | 35.4 | 100 | 14
18 | 36.3 | 15 | 36.2 | 100 | 14
19 | 36.5 | 15 | 35.4 | 97 | 14
20 | 37.5 | 15 | 36.4 | 97 | 14
21 | 37.9 | 15 | 36.7 | 97 | 14
22 | 38.4 | 15 | 36.6 | 95 | 14
23 | 39.0 | 15 | 37.4 | 96 | 14
24 | 39.4 | 15 | 37.9 | 96 | 14
25 | 40.0 | 15 | 38.5 | 96 | 14
26 | 40.2 | 15 | 38.5 | 96 | 14
27 | 38.5 | 15 | 39.1 | 102 | 14
28 | 39.2 | 15 | 38.3 | 98 | 14
29 | 38.3 | 15 | 38.8 | 101 | 14
30 | 39.5 | 15 | 39.1 | 99 | 14
31 | 40.0 | 15 | 39.3 | 98 | 14
32 | 41.2 | 15 | 37.9 | 92 | 14
33 | 40.6 | 15 | 40.1 | 99 | 14
34 | 41.0 | 15 | 39.8 | 97 | 14
35 | 40.2 | 15 | 39.8 | 99 | 14
36 | 41.1 | 15 | 40.3 | 98 | 14
37 | 42.1 | 15 | 38.0 | 90 | 14
38 | 41.6 | 15 | 38.2 | 92 | 14
39 | 41.8 | 15 | 40.5 | 97 | 14
40 | 41.5 | 15 | 39.7 | 96 | 14
Mean for Weeks
1-13 | 29.5 | | 29.9 | 101
14-40 | 38.9 | | 37.8 | 97

TABLE 7 Mean Body Weights and Survival of Female FVB/N Mice in the 40-Week Gavage Study of Allyl Bromide

Weeks on Study | Vehicle Control | | 8 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 19.6 | 15 | 20.5 | 105 | 15
2 | 20.7 | 15 | 21.4 | 103 | 15
3 | 19.8 | 15 | 22.1 | 112 | 15
4 | 19.9 | 15 | 22.1 | 111 | 15
5 | 21.5 | 15 | 22.9 | 107 | 15
6 | 22.0 | 15 | 23.4 | 106 | 15
7 | 22.9 | 15 | 23.2 | 101 | 15
8 | 23.2 | 15 | 23.6 | 102 | 15
9 | 22.8 | 15 | 23.9 | 105 | 15
10 | 23.7 | 15 | 24.8 | 105 | 15
11 | 23.6 | 15 | 24.9 | 106 | 15
12 | 24.1 | 15 | 25.6 | 106 | 15
13 | 24.2 | 15 | 25.9 | 107 | 15
14 | 23.1 | 15 | 25.9 | 112 | 15
15 | 24.9 | 15 | 26.2 | 105 | 15
16 | 24.8 | 15 | 27.3 | 110 | 15
17 | 25.5 | 15 | 26.1 | 102 | 15
18 | 26.5 | 15 | 27.1 | 102 | 15
19 | 26.3 | 15 | 28.0 | 107 | 15
20 | 26.6 | 15 | 28.6 | 108 | 15
21 | 26.4 | 15 | 28.9 | 110 | 15
22 | 27.1 | 15 | 28.8 | 106 | 15
23 | 27.3 | 15 | 29.0 | 106 | 15
24 | 27.5 | 15 | 29.6 | 108 | 15
25 | 28.4 | 15 | 29.3 | 103 | 15
26 | 28.5 | 15 | 29.4 | 103 | 15
27 | 27.0 | 15 | 29.8 | 110 | 15
28 | 27.9 | 15 | 30.9 | 111 | 15
29 | 28.6 | 15 | 30.5 | 107 | 15
30 | 29.2 | 15 | 31.0 | 106 | 15
31 | 29.4 | 15 | 30.9 | 105 | 15
32 | 29.0 | 15 | 30.3 | 105 | 14
33 | 30.1 | 15 | 31.6 | 105 | 14
34 | 30.1 | 15 | 31.0 | 103 | 14
35 | 29.6 | 15 | 31.0 | 105 | 14
36 | 30.6 | 15 | 31.6 | 103 | 14
37 | 32.0 | 15 | 30.8 | 96 | 14
38 | 31.5 | 15 | 30.7 | 98 | 14
39 | 31.9 | 15 | 32.0 | 100 | 14
40 | 32.5 | 15 | 33.4 | 103 | 14
Mean for Weeks
1-13 | 22.2 | | 23.4 | 106
14-40 | 28.2 | | 29.6 | 105

## 40-Week Gavage Study in Tg.AC Hemizygous Mice

### Positive Control Tg.AC Hemizygous Mice

12-O-Tetradecanoylphorbol-13-acetate (1.25 µg) was dermally administered to groups of 15 male and 15 female mice. Except for one female that died early, all males and females developed more than 20 skin papillomas each by week 18 (data not shown). This is consistent with historical rates found in other studies and indicates that the Tg.AC mice in this entire study were of the “responder” genotype (Tennant et al., 2001).

### Survival

Estimates of 40-week survival probabilities for male and female mice are shown in Table 8. Survival of dosed mice was similar to that of the vehicle control groups.

### Body Weights, Clinical Findings, and Organ Weights

Mean body weights of dosed mice were generally similar to those of the vehicle control mice throughout the study (Figure 3; Tables 9 and 10). There were no treatment-related clinical findings in male mice. In female mice, there were increased numbers of cutaneous and mucocutaneous masses (gross observations) on the body, particularly the vaginal and vulvar area, and these papillomas were observed earlier in the dosed groups. There were no biologically significant differences in organ weights of dosed groups compared to the vehicle control groups (Table F3).

TABLE 8 Survival of Tg.AC Hemizygous Mice in the 40-Week Gavage Study of Allyl Bromide

| Vehicle Control | 0.5 mg/kg | 1 mg/kg | 2 mg/kg | 4 mg/kg | 8 mg/kg
Male
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Accidental deaths^a^ | 0 | 1 | 0 | 1 | 1 | 1
Moribund | 2 | 2 | 3 | 2 | 4 | 1
Natural deaths | 1 | 3 | 3 | 0 | 4 | 2
Animals surviving to study termination | 12 | 9 | 9 | 12 | 6 | 11
Percent probability of survival at end of study^b^ | 80 | 64 | 60 | 86 | 43 | 79
Mean survival (days)^c^ | 264 | 228 | 227 | 241 | 213 | 233
Survival analysis^d^ | P=1.000 | P=0.480 | P=0.304 | P=1.000N | P=0.055 | P=1.000
Female
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Accidental deaths^a^ | 2 | 0 | 0 | 0 | 0 | 0
Moribund | 2 | 3 | 4 | 6 | 1 | 3
Natural deaths | 2 | 2 | 3 | 1 | 3 | 0
Animals surviving to study termination | 9 | 10 | 8 | 8 | 11 | 12
Percent probability of survival at end of study | 71 | 67 | 53 | 53 | 73 | 80
Mean survival (days) | 247 | 246 | 232 | 245 | 248 | 267
Survival analysis | P=0.265N | P=1.000 | P=0.454 | P=0.524 | P=1.000N | P=0.816N

a Censored from survival analysis

b Kaplan-Meier determinations

c Mean of all deaths (uncensored, censored, and terminal sacrifice)

d The result of the life table trend test (Tarone, 1975) is in the vehicle control column, and the results of the life table pairwise comparisons (Cox, 1972) with the vehicle controls are in the dosed group columns. A negative trend or lower mortality in a dosed group is indicated by N.

FIGURE 3 Growth Curves for Male and Female Tg.AC Hemizygous Mice Exposed to Allyl Bromide by Gavage for 40 Weeks

TABLE 9 Mean Body Weights and Survival of Male Tg.AC Hemizygous Mice in the 40-Week Gavage Study of Allyl Bromide

Weeks on Study | Vehicle Control | | 0.5 mg/kg | | | 1 mg/kg | | | 2 mg/kg | | | 4 mg/kg | | | 8 mg/kg
Weeks on Study | Av. Wt (g) | No. of Survivors | Av. Wt (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 22.8 | 15 | 22.9 | 100 | 15 | 23.0 | 101 | 15 | 23.0 | 101 | 15 | 22.7 | 100 | 15 | 22.3 | 98 | 15
2 | 23.9 | 15 | 23.3 | 98 | 15 | 24.0 | 100 | 15 | 23.7 | 99 | 15 | 24.3 | 102 | 14 | 23.0 | 96 | 14
3 | 24.9 | 15 | 25.1 | 101 | 14 | 25.5 | 102 | 15 | 24.5 | 98 | 14 | 25.8 | 104 | 14 | 25.0 | 100 | 14
4 | 26.4 | 15 | 26.5 | 100 | 14 | 26.7 | 101 | 15 | 25.8 | 98 | 14 | 26.9 | 102 | 14 | 26.1 | 99 | 14
5 | 26.9 | 15 | 27.0 | 100 | 14 | 27.5 | 102 | 15 | 27.2 | 101 | 14 | 28.1 | 105 | 14 | 27.3 | 102 | 14
6 | 28.3 | 15 | 27.8 | 98 | 14 | 28.5 | 101 | 15 | 28.4 | 100 | 14 | 29.3 | 104 | 14 | 28.3 | 100 | 14
7 | 29.3 | 15 | 28.7 | 98 | 14 | 29.4 | 100 | 15 | 29.0 | 99 | 14 | 29.8 | 102 | 14 | 29.0 | 99 | 14
8 | 29.6 | 15 | 29.1 | 98 | 14 | 30.1 | 102 | 15 | 29.5 | 100 | 14 | 30.7 | 104 | 14 | 29.3 | 99 | 14
9 | 29.7 | 15 | 29.2 | 98 | 14 | 30.3 | 102 | 15 | 29.4 | 99 | 14 | 30.9 | 104 | 14 | 29.9 | 101 | 14
10 | 29.9 | 15 | 29.5 | 99 | 14 | 30.7 | 103 | 15 | 29.9 | 100 | 14 | 31.0 | 104 | 14 | 30.0 | 100 | 14
11 | 30.1 | 15 | 29.3 | 97 | 14 | 30.9 | 103 | 14 | 30.3 | 101 | 14 | 31.2 | 104 | 14 | 30.4 | 101 | 14
12 | 31.0 | 15 | 30.5 | 98 | 14 | 31.9 | 103 | 14 | 31.4 | 101 | 14 | 32.2 | 104 | 14 | 31.0 | 100 | 14
13 | 30.7 | 15 | 31.0 | 101 | 14 | 32.3 | 105 | 14 | 31.0 | 101 | 14 | 32.6 | 106 | 14 | 31.6 | 103 | 14
14 | 31.3 | 15 | 31.7 | 101 | 14 | 33.0 | 105 | 14 | 32.0 | 102 | 14 | 33.1 | 106 | 14 | 32.3 | 103 | 14
15 | 32.6 | 15 | 31.6 | 97 | 14 | 32.6 | 100 | 14 | 32.1 | 99 | 14 | 33.4 | 103 | 14 | 33.0 | 101 | 14
16 | 33.3 | 15 | 31.8 | 96 | 14 | 33.4 | 100 | 14 | 32.9 | 99 | 14 | 33.7 | 101 | 14 | 32.4 | 97 | 14
17 | 33.3 | 15 | 31.4 | 94 | 14 | 33.0 | 99 | 14 | 33.0 | 99 | 14 | 34.0 | 102 | 14 | 32.5 | 98 | 12
18 | 33.9 | 15 | 31.0 | 91 | 14 | 33.5 | 99 | 13 | 33.7 | 99 | 14 | 34.7 | 102 | 14 | 33.6 | 99 | 12
19 | 34.2 | 15 | 32.6 | 95 | 14 | 33.3 | 97 | 13 | 33.5 | 98 | 14 | 34.1 | 100 | 13 | 33.8 | 99 | 12
20 | 34.5 | 15 | 32.6 | 95 | 14 | 33.7 | 98 | 13 | 33.9 | 98 | 14 | 34.9 | 101 | 12 | 34.0 | 99 | 12
21 | 34.7 | 15 | 32.6 | 94 | 14 | 34.4 | 99 | 13 | 34.4 | 99 | 14 | 35.4 | 102 | 12 | 34.7 | 100 | 12
22 | 35.2 | 15 | 33.9 | 96 | 14 | 34.7 | 99 | 13 | 35.3 | 100 | 13 | 35.7 | 101 | 12 | 35.0 | 99 | 12
23 | 34.9 | 15 | 34.2 | 98 | 14 | 35.5 | 102 | 12 | 35.7 | 102 | 13 | 36.2 | 104 | 12 | 35.4 | 101 | 12
24 | 35.3 | 15 | 33.6 | 95 | 14 | 35.6 | 101 | 12 | 36.1 | 102 | 13 | 35.9 | 102 | 12 | 35.8 | 101 | 12
25 | 35.6 | 15 | 32.9 | 92 | 12 | 37.0 | 104 | 11 | 36.4 | 102 | 12 | 36.4 | 102 | 11 | 36.5 | 103 | 12
26 | 37.3 | 14 | 34.1 | 91 | 12 | 37.2 | 100 | 11 | 36.7 | 98 | 12 | 36.3 | 97 | 11 | 36.0 | 97 | 12
27 | 36.5 | 14 | 34.3 | 94 | 12 | 37.0 | 101 | 11 | 37.1 | 102 | 12 | 36.5 | 100 | 11 | 36.7 | 101 | 12
28 | 35.7 | 14 | 35.1 | 98 | 11 | 37.5 | 105 | 11 | 36.9 | 103 | 12 | 36.7 | 103 | 11 | 36.7 | 103 | 12
29 | 37.1 | 14 | 35.2 | 95 | 11 | 37.3 | 101 | 11 | 36.8 | 99 | 12 | 36.2 | 98 | 11 | 36.5 | 98 | 12
30 | 36.8 | 14 | 35.1 | 95 | 11 | 37.7 | 102 | 11 | 36.8 | 100 | 12 | 35.8 | 97 | 10 | 36.9 | 100 | 12
31 | 37.0 | 14 | 34.6 | 94 | 10 | 39.8 | 108 | 10 | 36.6 | 99 | 12 | 36.0 | 97 | 10 | 36.9 | 100 | 12
32 | 34.8 | 14 | 33.2 | 95 | 10 | 37.2 | 107 | 10 | 35.7 | 103 | 12 | 35.9 | 103 | 10 | 36.3 | 104 | 12
33 | 35.8 | 14 | 34.1 | 95 | 9 | 37.7 | 105 | 10 | 36.4 | 102 | 12 | 35.2 | 98 | 8 | 36.4 | 102 | 12
34 | 36.0 | 14 | 34.6 | 96 | 9 | 39.1 | 109 | 9 | 36.9 | 103 | 12 | 34.2 | 95 | 8 | 35.8 | 99 | 12
35 | 35.4 | 14 | 32.7 | 92 | 9 | 36.3 | 103 | 9 | 37.4 | 106 | 12 | 33.3 | 94 | 7 | 36.2 | 102 | 12
36 | 36.9 | 12 | 33.8 | 92 | 9 | 38.9 | 105 | 9 | 35.8 | 97 | 12 | 36.5 | 99 | 6 | 36.7 | 100 | 11
37 | 37.1 | 12 | 35.9 | 97 | 9 | 39.8 | 107 | 9 | 37.3 | 101 | 12 | 37.2 | 100 | 6 | 38.3 | 103 | 11
38 | 38.1 | 12 | 36.5 | 96 | 9 | 39.8 | 105 | 9 | 36.2 | 95 | 12 | 36.1 | 95 | 6 | 38.8 | 102 | 11
39 | 39.1 | 12 | 36.4 | 93 | 9 | 38.5 | 99 | 9 | 36.8 | 94 | 12 | 36.5 | 93 | 6 | 39.2 | 100 | 11
40 | 39.1 | 12 | 36.4 | 93 | 9 | 39.2 | 100 | 9 | 36.8 | 94 | 12 | 37.7 | 96 | 6 | 38.4 | 98 | 11
Mean for Weeks
1-13 | 28.0 | | 27.7 | 99 | | 28.5 | 102 | | 27.9 | 100 | | 28.9 | 103 | | 27.9 | 100
14-40 | 35.6 | | 33.8 | 95 | | 36.4 | 102 | | 35.5 | 100 | | 35.5 | 100 | | 35.7 | 100

TABLE 10 Mean Body Weights and Survival of Female Tg.AC Hemizygous Mice in the 40-Week Gavage Study of Allyl Bromide

Weeks on Study | Vehicle Control | | 0.5 mg/kg | | | 1 mg/kg | | | 2 mg/kg | | | 4 mg/kg | | | 8 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 18.6 | 15 | 18.5 | 100 | 15 | 18.9 | 102 | 15 | 18.9 | 102 | 15 | 18.8 | 101 | 15 | 18.3 | 98 | 15
2 | 19.3 | 15 | 19.0 | 98 | 15 | 19.2 | 100 | 15 | 19.5 | 101 | 15 | 19.5 | 101 | 15 | 19.2 | 100 | 15
3 | 19.5 | 15 | 19.5 | 100 | 15 | 19.9 | 102 | 15 | 19.9 | 102 | 15 | 20.0 | 103 | 15 | 19.9 | 102 | 15
4 | 20.4 | 15 | 20.3 | 100 | 15 | 20.4 | 100 | 15 | 19.7 | 97 | 15 | 21.0 | 103 | 15 | 20.5 | 101 | 15
5 | 20.6 | 15 | 20.5 | 100 | 15 | 20.9 | 102 | 15 | 21.0 | 102 | 15 | 21.2 | 103 | 15 | 21.2 | 103 | 15
6 | 21.5 | 15 | 21.5 | 100 | 15 | 22.0 | 102 | 15 | 21.9 | 102 | 15 | 22.1 | 103 | 15 | 22.4 | 104 | 15
7 | 21.8 | 15 | 21.9 | 101 | 15 | 22.2 | 102 | 15 | 22.5 | 103 | 15 | 22.7 | 104 | 15 | 22.7 | 104 | 15
8 | 22.6 | 15 | 22.5 | 100 | 15 | 22.9 | 101 | 15 | 23.0 | 102 | 15 | 23.2 | 103 | 15 | 23.1 | 102 | 15
9 | 23.0 | 15 | 22.5 | 98 | 15 | 23.3 | 101 | 15 | 23.4 | 102 | 15 | 23.7 | 103 | 15 | 23.2 | 101 | 15
10 | 23.3 | 15 | 23.1 | 99 | 15 | 23.4 | 100 | 15 | 23.4 | 100 | 15 | 23.8 | 102 | 15 | 23.8 | 102 | 15
11 | 24.1 | 15 | 23.0 | 95 | 15 | 23.8 | 99 | 15 | 24.1 | 100 | 15 | 23.9 | 99 | 15 | 24.3 | 101 | 15
12 | 24.5 | 15 | 23.7 | 97 | 15 | 24.2 | 99 | 15 | 23.9 | 98 | 15 | 24.6 | 100 | 15 | 24.8 | 101 | 15
13 | 24.9 | 15 | 24.3 | 98 | 15 | 24.7 | 99 | 15 | 24.5 | 98 | 15 | 25.1 | 101 | 15 | 25.2 | 101 | 15
14 | 24.8 | 15 | 24.5 | 99 | 15 | 25.1 | 101 | 15 | 24.3 | 98 | 15 | 25.2 | 102 | 14 | 25.4 | 102 | 15
15 | 25.2 | 15 | 24.4 | 97 | 15 | 25.2 | 100 | 15 | 25.1 | 100 | 15 | 25.7 | 102 | 14 | 26.0 | 103 | 15
16 | 25.6 | 15 | 24.3 | 95 | 15 | 24.9 | 97 | 14 | 26.3 | 103 | 15 | 26.4 | 103 | 14 | 26.4 | 103 | 15
17 | 25.8 | 15 | 25.3 | 98 | 15 | 24.9 | 97 | 14 | 26.1 | 101 | 15 | 26.6 | 103 | 14 | 26.2 | 102 | 15
18 | 26.0 | 15 | 25.7 | 99 | 15 | 25.6 | 99 | 14 | 26.7 | 103 | 15 | 26.7 | 103 | 14 | 26.9 | 104 | 15
19 | 25.7 | 15 | 25.9 | 101 | 15 | 25.5 | 99 | 14 | 26.4 | 103 | 15 | 27.2 | 106 | 14 | 26.9 | 105 | 15
20 | 26.1 | 15 | 25.9 | 99 | 15 | 25.5 | 98 | 14 | 26.8 | 103 | 15 | 27.2 | 104 | 14 | 27.2 | 104 | 15
21 | 26.3 | 15 | 26.2 | 100 | 15 | 26.2 | 100 | 14 | 27.9 | 106 | 14 | 27.2 | 103 | 14 | 28.0 | 107 | 15
22 | 26.9 | 15 | 27.0 | 100 | 14 | 26.1 | 97 | 14 | 27.7 | 103 | 14 | 27.7 | 103 | 14 | 27.5 | 102 | 15
23 | 27.4 | 13 | 27.1 | 99 | 14 | 26.9 | 98 | 13 | 28.1 | 103 | 14 | 28.0 | 102 | 14 | 28.2 | 103 | 15
24 | 27.3 | 13 | 27.4 | 100 | 14 | 27.3 | 100 | 13 | 28.1 | 103 | 14 | 28.4 | 104 | 14 | 28.5 | 104 | 15
25 | 27.8 | 13 | 27.8 | 100 | 13 | 27.7 | 100 | 12 | 29.0 | 104 | 14 | 28.7 | 103 | 14 | 29.2 | 105 | 15
26 | 27.7 | 13 | 27.9 | 101 | 13 | 28.0 | 101 | 12 | 28.8 | 104 | 14 | 28.2 | 102 | 14 | 28.9 | 104 | 15
27 | 28.1 | 13 | 28.2 | 100 | 13 | 28.2 | 100 | 12 | 28.3 | 101 | 14 | 28.6 | 102 | 14 | 29.3 | 104 | 15
28 | 29.1 | 13 | 29.3 | 101 | 13 | 28.3 | 97 | 12 | 28.7 | 99 | 14 | 29.7 | 102 | 13 | 30.1 | 103 | 15
29 | 28.9 | 13 | 28.9 | 100 | 13 | 29.2 | 101 | 10 | 29.4 | 102 | 12 | 28.9 | 100 | 13 | 28.7 | 99 | 15
30 | 28.8 | 13 | 30.0 | 104 | 12 | 29.5 | 102 | 10 | 29.3 | 102 | 12 | 30.3 | 105 | 12 | 29.3 | 102 | 15
31 | 28.9 | 13 | 30.1 | 104 | 12 | 29.5 | 102 | 10 | 29.3 | 101 | 12 | 30.0 | 104 | 12 | 29.3 | 101 | 15
32 | 28.5 | 11 | 29.2 | 103 | 12 | 28.4 | 100 | 10 | 29.2 | 103 | 11 | 29.6 | 104 | 11 | 28.8 | 101 | 14
33 | 29.5 | 11 | 30.8 | 104 | 10 | 29.0 | 98 | 10 | 29.6 | 100 | 11 | 30.0 | 102 | 11 | 29.4 | 100 | 14
34 | 30.2 | 10 | 30.9 | 102 | 10 | 28.7 | 95 | 10 | 29.3 | 97 | 11 | 30.5 | 101 | 11 | 29.4 | 97 | 14
35 | 30.1 | 10 | 31.3 | 104 | 10 | 28.5 | 95 | 9 | 27.9 | 93 | 11 | 30.0 | 100 | 11 | 29.1 | 97 | 14
36 | 30.2 | 10 | 31.2 | 103 | 10 | 28.6 | 95 | 9 | 30.2 | 100 | 9 | 30.5 | 101 | 11 | 30.2 | 100 | 13
37 | 31.4 | 10 | 33.0 | 105 | 10 | 30.2 | 96 | 8 | 32.6 | 104 | 8 | 31.5 | 100 | 11 | 31.8 | 101 | 12
38 | 31.3 | 10 | 32.6 | 104 | 10 | 30.0 | 96 | 8 | 32.2 | 103 | 8 | 31.9 | 102 | 11 | 31.7 | 101 | 12
39 | 30.7 | 9 | 32.2 | 105 | 10 | 29.6 | 96 | 8 | 31.6 | 103 | 8 | 31.4 | 102 | 11 | 31.7 | 103 | 12
40 | 30.2 | 9 | 31.6 | 105 | 10 | 30.4 | 101 | 8 | 31.4 | 104 | 8 | 31.7 | 105 | 11 | 32.2 | 107 | 12
Mean for Weeks
1-13 | 21.9 | | 21.6 | 99 | | 22.0 | 101 | | 22.0 | 101 | | 22.3 | 102 | | 22.2 | 102
14-40 | 28.1 | | 28.5 | 101 | | 27.7 | 99 | | 28.5 | 102 | | 28.8 | 103 | | 28.8 | 102

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms of the skin. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Appendix B for male and female Tg.AC hemizygous mice.

Skin: The incidences of squamous cell papilloma of the vulva increased with a positive trend (P=0.018) (Tables 11 and B3). The incidences of squamous cell papilloma at all skin sites (including vulva) also increased with a positive trend (P≤0.05). Squamous cell papillomas of the vulva tended to be larger in treated mice (1 to 7 mm in greatest diameter; average diameter was 2.3 mm) than those in control mice (1 mm or less in greatest diameter). Size of papillomas did not seem to increase with increasing dose (data not shown).

TABLE 11 Incidences of Skin Neoplasms in Female Tg.AC Hemizygous Mice in the 40-Week Gavage Study of Allyl Bromide

| Vehicle Control | 0.5 mg/kg | 1 mg/kg | 2 mg/kg | 4 mg/kg | 8 mg/kg
Number Examined Microscopically | 15 | 15 | 15 | 15 | 14 | 15
Vulva, Squamous Cell Papilloma, Multiple^a^ | 0 | 0 | 0 | 1 | 1 | 1
Vulva, Squamous Cell Papilloma^b,c^ (includes multiple) | 2 | 4 | 1 | 6 | 5 | 7
All Sites, Squamous Cell Papilloma^c,d^ | 4 | 6 | 3 | 7 | 8 | 9

a Number of animals with neoplasm

b Historical incidence for control Tg.AC female mice from 39- to 41-week studies (all routes): 3/99 (3%)

c Statistically significant (P≤0.05) by the Cochran-Armitage trend test (Armitage, 1971)

d Historical incidence for Tg.AC female mice: 43/99 (43%)

## 40-Week Gavage Study in C57BL/6 Mice

### Survival

Estimates of 40-week survival probabilities for male and female mice are shown in Table 12. Survival of dosed mice was similar to that of the vehicle control groups, although three 8 mg/kg females died early.

### Body Weights, Clinical Findings, and Organ Weights

Mean body weights were similar between dosed and vehicle control mice (Tables 13 and 14; Figure 4). There were no treatment-related clinical findings. There were no statistically significant differences in organ weights between the dosed and vehicle control groups (Table F5).

### Pathology and Statistical Analyses

There were no chemical-related gross or microscopic findings in C57BL/6 mice administered allyl bromide for 40 weeks. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Appendix C for male and female C57BL/6 mice.

TABLE 12 Survival of C57BL/6 Mice in the 40-Week Gavage Study of Allyl Bromide

| Vehicle Control | 8 mg/kg
Male
Animals initially in study | 15 | 15
Moribund | 1 | 0
Animals surviving to study termination | 14 | 15
Percent probability of survival at end of study^a^ | 93 | 100
Mean survival (days)^b^ | 279 | 280
Survival analysis^c^ | | P=1.000N
Female
Animals initially in study | 15 | 15
Moribund | 0 | 2
Natural deaths | 0 | 1
Animals surviving to study termination | 15 | 12
Percent probability of survival at end of study | 100 | 80
Mean survival (days) | 279 | 273
Survival analysis | | P=0.226

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice)

c The results of the life table pairwise comparisons (Cox, 1972) with the vehicle controls are in the dosed group column. Lower mortality in a dosed group is indicated by N.

TABLE 13 Mean Body Weights and Survival of Male C57BL/6 Mice in the 40-Week Gavage Study of Allyl Bromide

Weeks on Study | Vehicle Control | | 8 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 23.9 | 15 | 24.0 | 100 | 15
2 | 24.2 | 15 | 24.0 | 99 | 15
3 | 25.4 | 15 | 25.3 | 100 | 15
4 | 25.4 | 15 | 25.9 | 102 | 15
5 | 26.8 | 15 | 27.0 | 101 | 15
6 | 27.5 | 15 | 27.9 | 102 | 15
7 | 28.2 | 15 | 28.9 | 103 | 15
8 | 29.3 | 15 | 29.4 | 100 | 15
9 | 29.7 | 15 | 29.8 | 100 | 15
10 | 30.8 | 15 | 30.2 | 98 | 15
11 | 31.7 | 15 | 31.7 | 100 | 15
12 | 32.5 | 15 | 32.7 | 101 | 15
13 | 33.4 | 15 | 33.3 | 100 | 15
14 | 34.2 | 15 | 34.4 | 101 | 15
15 | 34.9 | 15 | 35.3 | 101 | 15
16 | 36.6 | 15 | 36.7 | 100 | 15
17 | 37.5 | 15 | 37.5 | 100 | 15
18 | 38.1 | 15 | 37.7 | 99 | 15
19 | 38.4 | 15 | 38.3 | 100 | 15
20 | 38.8 | 15 | 38.6 | 100 | 15
21 | 39.4 | 15 | 38.5 | 98 | 15
22 | 40.3 | 15 | 39.1 | 97 | 15
23 | 41.0 | 15 | 40.1 | 98 | 15
24 | 41.3 | 15 | 41.2 | 100 | 15
25 | 41.9 | 15 | 41.4 | 99 | 15
26 | 42.2 | 15 | 42.0 | 100 | 15
27 | 42.7 | 15 | 42.7 | 100 | 15
28 | 43.2 | 15 | 43.2 | 100 | 15
29 | 42.9 | 15 | 43.7 | 102 | 15
30 | 43.0 | 15 | 42.5 | 99 | 15
31 | 43.0 | 15 | 40.1 | 93 | 15
32 | 43.3 | 15 | 41.1 | 95 | 15
33 | 43.6 | 15 | 42.3 | 97 | 15
34 | 43.7 | 15 | 43.6 | 100 | 15
35 | 44.0 | 15 | 44.3 | 101 | 15
36 | 43.7 | 15 | 45.1 | 103 | 15
37 | 43.5 | 15 | 45.5 | 105 | 15
38 | 44.6 | 15 | 45.9 | 103 | 15
39 | 46.1 | 14 | 44.9 | 97 | 15
40 | 46.4 | 14 | 45.5 | 98 | 15
Mean for Weeks
1-13 | 28.4 | | 28.5 | 100
14-40 | 41.4 | | 41.2 | 99

TABLE 14 Mean Body Weights and Survival of Female C57BL/6 Mice in the 40-Week Gavage Study of Allyl Bromide

Weeks on Study | Vehicle Control | | 8 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 20.1 | 15 | 20.0 | 100 | 15
2 | 20.5 | 15 | 20.6 | 101 | 15
3 | 20.9 | 15 | 21.0 | 101 | 15
4 | 21.3 | 15 | 21.8 | 102 | 15
5 | 21.9 | 15 | 22.5 | 103 | 15
6 | 22.4 | 15 | 23.1 | 103 | 15
7 | 23.0 | 15 | 23.8 | 104 | 15
8 | 23.1 | 15 | 23.6 | 102 | 15
9 | 23.6 | 15 | 24.5 | 104 | 15
10 | 24.0 | 15 | 25.1 | 105 | 15
11 | 24.5 | 15 | 24.8 | 101 | 15
12 | 24.8 | 15 | 25.8 | 104 | 15
13 | 25.5 | 15 | 26.7 | 105 | 15
14 | 25.7 | 15 | 27.3 | 106 | 15
15 | 26.4 | 15 | 27.9 | 106 | 15
16 | 26.9 | 15 | 28.5 | 106 | 15
17 | 27.4 | 15 | 28.9 | 106 | 15
18 | 27.7 | 15 | 29.1 | 105 | 15
19 | 27.6 | 15 | 29.3 | 106 | 15
20 | 28.2 | 15 | 29.8 | 106 | 15
21 | 29.0 | 15 | 30.7 | 106 | 15
22 | 29.9 | 15 | 31.2 | 104 | 15
23 | 31.0 | 15 | 31.8 | 103 | 15
24 | 31.6 | 15 | 32.2 | 102 | 15
25 | 31.6 | 15 | 32.6 | 103 | 15
26 | 31.8 | 15 | 33.1 | 104 | 15
27 | 32.7 | 15 | 33.8 | 103 | 15
28 | 32.2 | 15 | 33.9 | 105 | 15
29 | 32.4 | 15 | 34.2 | 106 | 15
30 | 33.4 | 15 | 33.5 | 100 | 15
31 | 34.0 | 15 | 33.4 | 98 | 15
32 | 34.5 | 15 | 33.4 | 97 | 15
33 | 35.4 | 15 | 35.0 | 99 | 14
34 | 36.2 | 15 | 35.3 | 98 | 14
35 | 36.7 | 15 | 35.5 | 97 | 14
36 | 37.3 | 15 | 35.4 | 95 | 14
37 | 37.8 | 15 | 35.7 | 94 | 14
38 | 38.5 | 15 | 36.4 | 95 | 14
39 | 38.7 | 15 | 37.0 | 96 | 12
40 | 39.8 | 15 | 37.7 | 95 | 12
Mean for Weeks
1-13 | 22.7 | | 23.3 | 103
14-40 | 32.4 | | 32.7 | 101

FIGURE 4 Growth Curves for Male and Female C57BL/6 Mice Exposed to Allyl Bromide by Gavage for 40 Weeks

## 40-Week Gavage Study in p53 Haploinsufficient Mice

### Survival

Estimates of 40-week survival probabilities for male and female mice are shown in Table 15. Survival of dosed male and female mice was similar to that of the vehicle controls with no more than two deaths per group.

### Body Weights, Clinical Findings, and Organ Weights

Mean body weights of 0.5, 4, and 8 mg/kg males were marginally greater than those of the vehicle controls after week 9 of the study (Figure 5 and Table 16). Mean body weights of 8 mg/kg females were marginally greater than those of the vehicle controls after week 10, and those of 4 mg/kg females were generally less after week 21 (Figure 5 and Table 17). There were no treatment-related clinical findings. Relative kidney and heart weights of females administered 4 mg/kg were significantly greater than those of the vehicle control group (Table F6).

### Pathology and Statistical Analyses

There were no chemical-related gross or microscopic findings in p53 haploinsufficient mice administered allyl bromide for 40 weeks. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Appendix D for male and female p53 haploinsufficient mice.

TABLE 15 Survival of p53 Haploinsufficient Mice in the 40-Week Gavage Study of Allyl Bromide

| Vehicle Control | 0.5 mg/kg | 1 mg/kg | 2 mg/kg | 4 mg/kg | 8 mg/kg
Male
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Moribund | 0 | 0 | 0 | 0 | 1 | 0
Natural deaths | 0 | 1 | 0 | 0 | 1 | 0
Animals surviving to study termination | 15 | 14 | 15 | 15 | 13 | 15
Percent probability of survival at end of study^a^ | 100 | 93 | 100 | 100 | 87 | 100
Mean survival (days)^b^ | 274 | 272 | 274 | 274 | 271 | 274
Survival analysis^c^ | P=1.000 | P=1.000 | —^d^ | — | P=0.464 | —
Female
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Moribund | 2 | 1 | 2 | 0 | 0 | 1
Natural deaths | 0 | 0 | 0 | 1 | 0 | 1
Animals surviving to study termination | 13 | 14 | 13 | 14 | 15 | 13
Percent probability of survival at end of study | 87 | 93 | 87 | 93 | 100 | 87
Mean survival (days) | 272 | 275 | 271 | 275 | 277 | 276
Survival analysis | P=1.000N | P=0.984N | P=1.000 | P=0.984N | P=0.464N | P=1.000N

a Kaplan-Meier determination

b Mean of all deaths (uncensored, censored, and terminal sacrifice)

c The result of the life table trend test (Tarone, 1975) is in the vehicle control column, and the results of the life table pairwise comparisons (Cox, 1972) with the vehicle controls are in the dosed group columns. A negative trend or lower mortality in a dosed group is indicated by N.

d Value of statistic cannot be computed.

TABLE 16 Mean Body Weights and Survival of Male p53 Haploinsufficient Mice in the 40-Week Gavage Study of Allyl Bromide

Weeks on Study | Vehicle Control | | 0.5 mg/kg | | | 1 mg/kg | | | 2 mg/kg | | | 4 mg/kg | | | 8 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 24.6 | 15 | 25.2 | 102 | 15 | 24.3 | 99 | 15 | 24.6 | 100 | 15 | 24.9 | 101 | 15 | 25.1 | 102 | 15
2 | 25.0 | 15 | 25.0 | 100 | 15 | 24.3 | 97 | 15 | 24.9 | 100 | 15 | 25.1 | 100 | 15 | 25.2 | 101 | 15
3 | 25.6 | 15 | 25.7 | 100 | 15 | 25.6 | 100 | 15 | 25.8 | 101 | 15 | 26.1 | 102 | 15 | 26.1 | 102 | 15
4 | 26.4 | 15 | 27.2 | 103 | 15 | 25.7 | 97 | 15 | 26.3 | 100 | 15 | 27.1 | 103 | 15 | 27.0 | 102 | 15
5 | 27.2 | 15 | 28.6 | 105 | 15 | 26.9 | 99 | 15 | 27.6 | 102 | 15 | 28.4 | 104 | 15 | 28.1 | 103 | 15
6 | 27.8 | 15 | 29.0 | 104 | 15 | 27.7 | 100 | 15 | 28.0 | 101 | 15 | 28.8 | 104 | 15 | 28.9 | 104 | 15
7 | 29.0 | 15 | 29.8 | 103 | 15 | 28.6 | 99 | 15 | 29.3 | 101 | 15 | 29.2 | 101 | 15 | 30.0 | 103 | 15
8 | 29.8 | 15 | 31.3 | 105 | 15 | 29.6 | 99 | 15 | 30.4 | 102 | 15 | 30.7 | 103 | 15 | 31.2 | 105 | 15
9 | 30.6 | 15 | 32.3 | 106 | 15 | 30.8 | 101 | 15 | 30.6 | 100 | 15 | 32.2 | 105 | 15 | 32.1 | 105 | 15
10 | 31.5 | 15 | 33.6 | 107 | 15 | 31.6 | 100 | 15 | 31.9 | 101 | 15 | 33.6 | 107 | 15 | 33.2 | 105 | 15
11 | 32.3 | 15 | 34.6 | 107 | 15 | 32.4 | 100 | 15 | 33.2 | 103 | 15 | 34.6 | 107 | 15 | 33.9 | 105 | 15
12 | 33.0 | 15 | 35.3 | 107 | 15 | 33.6 | 102 | 15 | 34.2 | 104 | 15 | 35.5 | 108 | 15 | 34.9 | 106 | 15
13 | 34.0 | 15 | 36.0 | 106 | 15 | 34.7 | 102 | 15 | 35.2 | 104 | 15 | 36.5 | 107 | 15 | 35.6 | 105 | 15
14 | 34.7 | 15 | 36.9 | 106 | 15 | 35.7 | 103 | 15 | 35.9 | 104 | 15 | 37.3 | 108 | 15 | 36.6 | 106 | 15
15 | 35.8 | 15 | 38.1 | 106 | 15 | 36.5 | 102 | 15 | 36.9 | 103 | 15 | 38.2 | 107 | 15 | 37.9 | 106 | 15
16 | 36.7 | 15 | 39.0 | 106 | 15 | 37.9 | 103 | 15 | 37.5 | 102 | 15 | 39.3 | 107 | 15 | 38.9 | 106 | 15
17 | 37.3 | 15 | 39.9 | 107 | 15 | 38.7 | 104 | 15 | 38.3 | 103 | 15 | 39.8 | 107 | 15 | 39.8 | 107 | 15
18 | 37.9 | 15 | 41.1 | 108 | 15 | 39.4 | 104 | 15 | 39.4 | 104 | 15 | 39.9 | 105 | 15 | 40.6 | 107 | 15
19 | 38.5 | 15 | 41.6 | 108 | 15 | 39.8 | 103 | 15 | 39.8 | 103 | 15 | 39.7 | 103 | 15 | 41.2 | 107 | 15
20 | 39.2 | 15 | 42.2 | 108 | 15 | 40.2 | 103 | 15 | 40.2 | 103 | 15 | 40.1 | 102 | 15 | 41.6 | 106 | 15
21 | 39.7 | 15 | 42.8 | 108 | 15 | 41.1 | 104 | 15 | 40.7 | 103 | 15 | 41.7 | 105 | 15 | 42.0 | 106 | 15
22 | 40.6 | 15 | 43.4 | 107 | 15 | 41.8 | 103 | 15 | 41.3 | 102 | 15 | 42.2 | 104 | 15 | 42.8 | 105 | 15
23 | 41.1 | 15 | 44.2 | 108 | 15 | 42.8 | 104 | 15 | 42.1 | 102 | 15 | 43.2 | 105 | 15 | 43.4 | 106 | 15
24 | 41.5 | 15 | 44.7 | 108 | 15 | 43.3 | 104 | 15 | 42.6 | 103 | 15 | 43.9 | 106 | 15 | 44.0 | 106 | 15
25 | 41.7 | 15 | 45.2 | 108 | 15 | 43.6 | 105 | 15 | 42.9 | 103 | 15 | 44.0 | 106 | 15 | 44.5 | 107 | 15
26 | 42.4 | 15 | 45.4 | 107 | 15 | 44.3 | 105 | 15 | 43.3 | 102 | 15 | 44.7 | 105 | 15 | 45.1 | 106 | 15
27 | 42.9 | 15 | 45.5 | 106 | 15 | 44.6 | 104 | 15 | 43.6 | 102 | 15 | 44.9 | 105 | 15 | 45.7 | 107 | 15
28 | 43.4 | 15 | 45.7 | 105 | 15 | 44.9 | 104 | 15 | 44.2 | 102 | 15 | 45.5 | 105 | 15 | 46.0 | 106 | 15
29 | 43.9 | 15 | 46.6 | 106 | 15 | 44.7 | 102 | 15 | 45.0 | 103 | 15 | 45.9 | 105 | 15 | 46.0 | 105 | 15
30 | 43.5 | 15 | 46.6 | 107 | 15 | 44.8 | 103 | 15 | 45.3 | 104 | 15 | 46.4 | 107 | 15 | 46.4 | 107 | 15
31 | 44.1 | 15 | 46.7 | 106 | 15 | 45.4 | 103 | 15 | 45.5 | 103 | 15 | 46.7 | 106 | 15 | 46.9 | 106 | 15
32 | 44.0 | 15 | 47.0 | 107 | 15 | 46.1 | 105 | 15 | 46.0 | 105 | 15 | 46.0 | 105 | 15 | 47.6 | 108 | 15
33 | 44.7 | 15 | 48.0 | 107 | 15 | 46.9 | 105 | 15 | 46.3 | 104 | 15 | 47.8 | 107 | 14 | 48.2 | 108 | 15
34 | 44.7 | 15 | 48.4 | 108 | 15 | 46.8 | 105 | 15 | 45.9 | 103 | 15 | 46.6 | 104 | 14 | 48.1 | 108 | 15
35 | 45.2 | 15 | 49.2 | 109 | 14 | 47.8 | 106 | 15 | 46.8 | 104 | 15 | 46.8 | 104 | 14 | 49.3 | 109 | 15
36 | 45.6 | 15 | 49.2 | 108 | 14 | 47.2 | 104 | 15 | 46.4 | 102 | 15 | 47.1 | 103 | 14 | 49.4 | 108 | 15
37 | 45.8 | 15 | 49.9 | 109 | 14 | 47.9 | 105 | 15 | 45.0 | 98 | 15 | 47.9 | 105 | 14 | 49.2 | 107 | 15
38 | 46.7 | 15 | 50.1 | 107 | 14 | 48.6 | 104 | 15 | 46.2 | 99 | 15 | 48.6 | 104 | 14 | 49.5 | 106 | 15
39 | 46.8 | 15 | 50.0 | 107 | 14 | 49.2 | 105 | 15 | 47.8 | 102 | 15 | 49.3 | 105 | 14 | 50.2 | 107 | 15
40 | 47.5 | 15 | 49.4 | 104 | 14 | 49.9 | 105 | 15 | 48.7 | 103 | 15 | 49.8 | 105 | 13 | 50.5 | 106 | 15
Mean for Weeks
1-13 | 29.0 | | 30.3 | 104 | | 28.9 | 100 | | 29.4 | 101 | | 30.2 | 104 | | 30.1 | 104
14-40 | 42.1 | | 45.1 | 107 | | 43.7 | 104 | | 43.1 | 103 | | 44.2 | 105 | | 44.9 | 107

TABLE 17 Mean Body Weights and Survival of Female p53 Haploinsufficient Mice in the 40-Week Gavage Study of Allyl Bromide

Weeks on Study | Vehicle Control | | 0.5 mg/kg | | | 1 mg/kg | | | 2 mg/kg | | | 4 mg/kg | | | 8 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 20.0 | 15 | 20.1 | 101 | 15 | 19.6 | 98 | 15 | 20.1 | 101 | 15 | 20.1 | 101 | 15 | 19.9 | 100 | 15
2 | 20.2 | 15 | 20.2 | 100 | 15 | 19.6 | 97 | 15 | 20.2 | 100 | 15 | 20.3 | 101 | 15 | 20.3 | 101 | 15
3 | 21.0 | 15 | 21.0 | 100 | 15 | 20.6 | 98 | 15 | 20.8 | 99 | 15 | 21.0 | 100 | 15 | 20.8 | 99 | 15
4 | 22.1 | 15 | 21.9 | 99 | 15 | 21.1 | 96 | 15 | 21.4 | 97 | 15 | 21.6 | 98 | 15 | 21.3 | 96 | 15
5 | 22.4 | 15 | 22.5 | 100 | 15 | 22.1 | 99 | 15 | 22.1 | 99 | 15 | 22.3 | 100 | 15 | 22.3 | 100 | 15
6 | 22.6 | 15 | 22.7 | 100 | 15 | 22.3 | 99 | 15 | 22.3 | 99 | 15 | 22.8 | 101 | 15 | 22.9 | 101 | 15
7 | 23.2 | 15 | 22.9 | 99 | 15 | 22.9 | 99 | 15 | 22.7 | 98 | 15 | 23.0 | 99 | 15 | 23.1 | 100 | 15
8 | 23.6 | 15 | 23.7 | 100 | 15 | 23.4 | 99 | 15 | 22.8 | 97 | 15 | 23.3 | 99 | 15 | 23.7 | 100 | 15
9 | 24.0 | 15 | 23.9 | 100 | 15 | 23.9 | 100 | 15 | 23.9 | 100 | 15 | 24.0 | 100 | 15 | 24.6 | 103 | 15
10 | 24.6 | 15 | 24.6 | 100 | 15 | 24.5 | 100 | 15 | 24.3 | 99 | 15 | 23.9 | 97 | 15 | 25.1 | 102 | 15
11 | 24.6 | 15 | 25.6 | 104 | 15 | 25.0 | 102 | 15 | 24.8 | 101 | 15 | 24.7 | 100 | 15 | 25.9 | 105 | 15
12 | 25.3 | 15 | 25.8 | 102 | 15 | 25.8 | 102 | 15 | 25.3 | 100 | 15 | 25.1 | 99 | 15 | 26.7 | 106 | 15
13 | 25.7 | 15 | 26.5 | 103 | 15 | 26.5 | 103 | 15 | 25.8 | 100 | 15 | 25.6 | 100 | 15 | 27.9 | 109 | 15
14 | 26.2 | 15 | 26.7 | 102 | 15 | 26.5 | 101 | 15 | 26.6 | 102 | 15 | 26.1 | 100 | 15 | 28.4 | 108 | 15
15 | 27.3 | 15 | 28.0 | 103 | 15 | 27.5 | 101 | 15 | 27.4 | 100 | 15 | 27.0 | 99 | 15 | 29.7 | 109 | 15
16 | 27.8 | 15 | 28.2 | 101 | 15 | 28.8 | 104 | 15 | 28.1 | 101 | 15 | 27.3 | 98 | 15 | 30.5 | 110 | 15
17 | 28.7 | 15 | 29.1 | 101 | 15 | 29.4 | 102 | 15 | 28.7 | 100 | 15 | 27.5 | 96 | 15 | 31.4 | 109 | 15
18 | 29.0 | 15 | 30.0 | 103 | 15 | 30.0 | 103 | 15 | 29.3 | 101 | 15 | 27.9 | 96 | 15 | 32.0 | 110 | 15
19 | 29.7 | 15 | 31.0 | 104 | 15 | 29.8 | 100 | 15 | 29.5 | 99 | 15 | 28.2 | 95 | 15 | 32.4 | 109 | 15
20 | 30.7 | 15 | 31.8 | 104 | 15 | 30.3 | 99 | 15 | 30.2 | 98 | 15 | 29.1 | 95 | 15 | 33.6 | 109 | 15
21 | 31.3 | 15 | 32.5 | 104 | 15 | 31.3 | 100 | 15 | 31.0 | 99 | 15 | 29.8 | 95 | 15 | 34.5 | 110 | 15
22 | 32.6 | 15 | 33.2 | 102 | 15 | 32.0 | 98 | 15 | 31.6 | 97 | 15 | 30.0 | 92 | 15 | 35.4 | 109 | 15
23 | 33.4 | 15 | 33.8 | 101 | 15 | 33.1 | 99 | 15 | 32.8 | 98 | 15 | 30.7 | 92 | 15 | 36.3 | 109 | 15
24 | 33.8 | 15 | 34.5 | 102 | 15 | 33.8 | 100 | 15 | 33.1 | 98 | 15 | 31.1 | 92 | 15 | 37.2 | 110 | 15
25 | 34.1 | 15 | 34.8 | 102 | 15 | 34.3 | 101 | 15 | 33.3 | 98 | 15 | 31.1 | 91 | 15 | 37.6 | 110 | 15
26 | 34.4 | 15 | 35.7 | 104 | 15 | 34.8 | 101 | 15 | 34.1 | 99 | 15 | 31.7 | 92 | 15 | 38.1 | 111 | 15
27 | 35.3 | 15 | 36.2 | 103 | 15 | 35.3 | 100 | 15 | 34.5 | 98 | 15 | 32.3 | 92 | 15 | 39.1 | 111 | 15
28 | 36.2 | 15 | 37.3 | 103 | 15 | 35.9 | 99 | 15 | 35.0 | 97 | 15 | 32.9 | 91 | 15 | 39.7 | 110 | 15
29 | 36.7 | 15 | 38.3 | 104 | 15 | 36.2 | 99 | 15 | 35.8 | 98 | 15 | 33.9 | 92 | 15 | 40.4 | 110 | 15
30 | 36.8 | 15 | 38.1 | 104 | 15 | 36.1 | 98 | 15 | 36.4 | 99 | 15 | 34.0 | 92 | 15 | 41.0 | 111 | 15
31 | 36.4 | 15 | 38.6 | 106 | 15 | 36.2 | 100 | 15 | 36.7 | 101 | 15 | 33.9 | 93 | 15 | 41.1 | 113 | 15
32 | 36.4 | 15 | 39.5 | 109 | 15 | 36.6 | 101 | 15 | 37.1 | 102 | 15 | 34.6 | 95 | 15 | 42.0 | 115 | 15
33 | 37.6 | 14 | 40.1 | 107 | 15 | 38.2 | 102 | 14 | 37.0 | 98 | 15 | 35.1 | 93 | 15 | 42.2 | 112 | 15
34 | 37.9 | 14 | 39.8 | 105 | 15 | 38.1 | 101 | 14 | 37.4 | 99 | 15 | 35.4 | 93 | 15 | 41.8 | 110 | 15
35 | 38.3 | 14 | 40.1 | 105 | 15 | 39.9 | 104 | 13 | 37.8 | 99 | 15 | 36.2 | 95 | 15 | 42.0 | 110 | 15
36 | 39.6 | 14 | 40.5 | 102 | 15 | 41.0 | 104 | 13 | 38.3 | 97 | 15 | 36.3 | 92 | 15 | 42.0 | 106 | 15
37 | 40.2 | 14 | 42.5 | 106 | 14 | 41.7 | 104 | 13 | 39.0 | 97 | 14 | 36.6 | 91 | 15 | 41.1 | 102 | 15
38 | 42.5 | 13 | 43.3 | 102 | 14 | 42.6 | 100 | 13 | 40.2 | 95 | 14 | 37.1 | 87 | 15 | 41.8 | 98 | 15
39 | 42.7 | 13 | 43.4 | 102 | 14 | 42.7 | 100 | 13 | 41.5 | 97 | 14 | 37.7 | 88 | 15 | 42.4 | 99 | 15
40 | 43.0 | 13 | 43.4 | 101 | 14 | 43.8 | 102 | 13 | 40.3 | 94 | 14 | 37.7 | 88 | 15 | 45.2 | 105 | 13
Mean for Weeks
1-13 | 23.0 | | 23.2 | 101 | | 22.9 | 99 | | 22.8 | 99 | | 22.9 | 100 | | 23.4 | 102
14-40 | 34.8 | | 35.9 | 103 | | 35.0 | 101 | | 34.2 | 99 | | 32.3 | 93 | | 37.7 | 109

FIGURE 5 Growth Curves for Male and Female p53 Haploinsufficient Mice Exposed to Allyl Bromide by Gavage for 40 Weeks

## Genetic Toxicology

Allyl bromide was mutagenic in Salmonella typhimurium strain TA100, with and without Aroclor-induced rat or hamster liver S9 (Table E1). The concentration ranges tested were 10 to 1,000 µg/plate without S9 and 3 to 333 µg/plate with S9; significant increases in revertants occurred at concentrations of 100 µg/plate and above. The mutagenic response obtained in the absence of S9 was stronger than that observed with either rat or hamster liver S9. No mutagenicity was detected in the S. typhimurium strain TA98, with or without S9, over the same concentration ranges.

The frequency of micronucleated erythrocytes was assessed in each of the four mouse strains treated with allyl bromide for 40 weeks. Results in all four strains of mice were concluded to be negative; in addition, no significant, consistent changes in the percentage of polychromatic erythrocytes (reticulocytes) among total erythrocytes were observed in any of the four strains (Tables E2, E3, E4, and E5).

Some observations of note in these micronucleus tests include the small increase in micronucleated erythrocytes seen in the single dosed group (8 mg/kg) of female C57BL/6 mice that was evaluated for micronucleus frequency (Table E4). Although the P value was significant (≤0.05), these results were judged to be negative because the small increase represented less than half a micronucleus per 1,000 cells, which is not biologically relevant. In the male p53 haploinsufficient mice, one dosed group (1.0 mg/kg) showed a small but significant increase (P=0.0006) in micronucleated erythrocyte frequency, but none of the three higher doses showed an effect; therefore, this small increase at a single dose concentration in one sex, even though statistically significant (P≤0.005), was not considered sufficient evidence of the ability of allyl bromide to induce an effect in this assay.