# MATERIALS AND METHODS

## Procurement and Characterization

### Allyl Bromide

Allyl bromide was obtained from Fluka Chemical Corporation (Buchs, Switzerland) in one lot (330638) and from Aldrich Chemical Co. in one lot (03614HN). Lot 330638 was used in the 2-week studies, and lot 03614HN was used in the 40-week studies. Identity and purity analyses were conducted by the analytical chemistry laboratory, Midwest Research Institute (Kansas City, MO) and the study laboratory, BioReliance (Rockville, MD). Reports on analyses performed in support of the allyl bromide studies are on file at the National Institute of Environmental Health Sciences.

Both lots of allyl bromide, a clear, colorless liquid, were identified by the analytical chemistry laboratory using infrared and proton nuclear magnetic resonance (NMR) spectroscopy and by the study laboratory using infrared spectroscopy. All infrared and NMR spectra were consistent with the literature spectra and spectra of a reference standard from the same lot. The purity of each lot was determined by the analytical chemistry and study laboratories using gas chromatography (GC). For lot 330638, GC indicated one major peak and five impurities with a combined peak area of 0.7% relative to the total peak area. GC by a second system indicated one major peak and three impurities with a combined peak area of less than 0.5%. The relative purity was 102% when compared to a reference standard from the same lot. The overall purity of lot 330638 was greater than 99%. For lot 03614HN, GC indicated one major peak and four impurities with a combined peak area of 0.45% relative to the total peak area. GC by a second system indicated one major peak and three impurities with a total combined area less than 0.3% of the total peak area. The relative purity was 102% when compared to a frozen reference from the same lot. The overall purity of lot 03614HN was greater than 99%. During the 40-week studies, additional purity analyses were performed by the study laboratory at 26 weeks and at the end of the study using GC.

To ensure stability, the bulk chemical was stored in a sealed container under a nitrogen headspace, protected from light, at 2° to 8° C. No degradation of the bulk chemical was detected.

### Acetone

ACS-grade acetone was obtained from Fisher Scientific (Hampton, NH) in two lots (963514 and 982335) that were used as the vehicle in the 2-week dermal study. The study laboratory determined the identity using infrared spectroscopy and the purity using GC. Infrared spectra were consistent with a literature spectrum. GC indicated a major peak; two impurities of 0.15% and 0.05% of the total peak area; several minor impurities, each less than 0.01% of the total peak area; and an overall purity greater than 99.7%.

### Corn Oil

Corn oil in multiple lots was used as the vehicle during the 2-week and 40-week gavage studies. The study laboratory analyzed peroxide levels prior to use and monthly during the study using potentiometric titration; all peroxide concentrations were less than 3 mEq/kg.

## Preparation and Analysis of Dose Formulations

For the 2-week dermal study, the dose formulations were prepared once by pipetting the appropriate amounts of allyl bromide and acetone into a volumetric flask and mixing thoroughly (Table G2). The dose formulations were stored in amber glass vials under a headspace of inert gas, protected from light, at 2° to 8° C for at least 35 days.

Prior to the 2-week dermal study, the analytical chemistry laboratory conducted stability studies on 1 mg/mL formulations of allyl bromide in acetone using GC. Formulations were stored in glass vials capped with Teflon^®^-lined septa, protected from light, at 25° and 5° C, and at simulated animal room conditions. Stability was confirmed for at least 35 days at 25° and 5° C and for at least 3 hours at animal room conditions.

For the 2-week and 40-week gavage studies, the appropriate amounts of allyl bromide and corn oil were pipetted into a volumetric flask and mixed thoroughly. Dose formulations were prepared once for the 2-week study and every 2 weeks during the 40-week studies. Dose formulations were stored in amber glass vials with Teflon^®^-lined septa and aluminum crimp caps under a headspace of inert gas, protected from light, at 2° to 8° C for up to 21 days, with the exception of formulations used between November 16, 1999, and December 20, 1999, which were stored for 27 days. Dose formulations prepared on December 7, 1999, stored at 2° to 8° C for 28 days, then at −20° C until analyzed on January 13, 2000, confirmed stability for up to 28 days (Table G3).

A solubility study of allyl bromide in corn oil was conducted by the analytical chemistry laboratory using GC; the maximum solubility was 142.2 mg/mL. No homogeneity studies were conducted on dose formulations in corn oil as concentrations used in the 2-week study (0.75 to 12.0 mg/mL) and 40-week studies (0.05 to 0.80 mg/mL) were well below the maximum solubility.

For the 2-week and 40-week gavage studies, the analytical chemistry laboratory conducted stability studies on 0.37 mg/mL formulations of allyl bromide in corn oil using GC. Formulations were stored in amber glass vials capped with Teflon^®^-lined septa, protected from light, at 25° and 5° C, and at simulated animal room conditions. Stability was confirmed for at least 16 days at 25° C, at least 21 days at 5° C, and at least 3 hours at animal room conditions. Later, a second stability study was conducted by the analytical chemistry laboratory on 0.74 mg/mL formulations under the same conditions as those previously described. No significant trend toward loss was observed at 25° or 5° C for at least 42 days, though variability was large (RSD 10.8%), and no significant loss was observed at animal room conditions for at least 3 hours.

Periodic analyses of the dose formulations were conducted by the study laboratory using GC. For the 2-week dermal and gavage studies, the dose formulations were analyzed once. Animal room samples were also analyzed. Of the dose formulations used and analyzed for the dermal study, all five were within 10% of the target concentrations; all five animal room samples were within 10% of target concentrations (Table G4). Of the dose formulations used and analyzed for the 2-week gavage study, all five were within 10% of the target concentrations; one of five animal room samples was within 10% of the target concentrations (Table G5). For the 40-week gavage studies, dose formulations were analyzed at least every 12 weeks; animal room samples were also analyzed. Of the dose formulations used and analyzed, all 25 were within 10% of the target concentrations; 17 of 30 animal room samples were within 10% of the target concentrations (Table G3).

## Study Designs

### Dose Selection Rationale

The 2-week studies were conducted in the parent strains of the Tg.AC hemizygous and p53 haploinsufficient mice, which were FVB/N and C57BL/6 mice, respectively. Allyl bromide was administered by gavage and dermal routes of administration to C57BL/6 and FVB/N mice, respectively. The gavage route was selected because the National Toxicology Program (NTP) had considered the gastrointestinal tract to be the target organ in previous studies of other brominated chemicals (NTP, 2006). Because of the limited water solubility of allyl bromide, corn oil was used as the gavage vehicle. The dermal route was used to mimic potential workplace exposure. The doses for the 2-week studies were based on an oral LD_50_ in rats of 120 mg/kg. No oral LD_50_ for mice was reported in the literature (RTECS, 2002). The intraperitoneal LD_50_ for mice was reported to be 108 mg/kg (Lewis, 1996). The dose concentrations selected for the 2-week studies were 0, 7.5, 15, 30, 60, and 120 mg/kg for gavage doses of allyl bromide (in corn oil) to C57BL/6 mice and dermal doses of allyl bromide (in acetone) to FVB/N mice.

### 2-Week Dermal Study

Groups of five male and five female FVB/N mice received dermal applications of 0, 7.5, 15, 30, 60, or 120 mg allyl bromide/kg body weight in 3.3 mL acetone/kg body weight, 5 days per week for 16 days. Vehicle control mice were administered acetone only. Doses were applied to the clipped dorsal skin from the mid-back to the interscapular area.

### 2-Week Gavage Study

Groups of five male and five female C57BL/6 mice received 0, 7.5, 15, 30, 60, or 120 mg allyl bromide/kg body weight in 10 mL corn oil/kg body weight by gavage, 5 days per week for 16 days. Vehicle control mice received corn oil only.

### 40-Week Gavage Studies

Groups of 15 male and 15 female FVB/N and C57BL/6 mice received 0 or 8 mg allyl bromide/kg body weight in corn oil by gavage, in a volume of 10 mL/kg body weight, 5 days per week for 40 weeks. Groups of 15 male and 15 female Tg.AC hemizygous and p53 haploinsufficient mice received 0, 0.5, 1, 2, 4, or 8 mg allyl bromide/kg body weight in 10 mL/kg corn oil by gavage, 5 days per week for 40 weeks. Vehicle control mice received corn oil only.

### Positive Control Mice

Positive control groups of 15 male and 15 female Tg.AC hemizygous mice received dermal applications of 1.25 µg TPA in 100 µL acetone (12.5 µg TPA/L solution), three times per week until removal from study. Positive control mice were removed after the appearance of 20 or more skin papillomas and discarded. The TPA solution was applied to the clipped dorsal skin from the mid-back to the interscapular area.

### Source and Specification of Animals

Male and female FVB/N, C57BL/6, Tg.AC hemizygous, and p53 haploinsufficient mice were obtained from Taconic Farms, Inc. (Germantown, NY), for use in the 2-week and 40-week studies. FVB/N and C57BL/6 mice were quarantined for 14 or 15 days, respectively, before the beginning of the 2-week studies. FVB/N and Tg.AC hemizygous mice were quarantined for 11 or 12 days and C57BL/6 and p53 haploinsufficient mice were quarantined for 12 days before the beginning of the 40-week studies. Before the 2-week and 40-week studies, five male and five female mice per strain were randomly selected for parasite evaluations and gross observations of disease. FVB/N and C57BL/6 mice were 7 or 8 weeks old, respectively, at the beginning of the 2-week studies. FVB/N, Tg.AC hemizygous, C57BL/6, and p53 haploinsufficient mice were 7, 6, 9, and 9 weeks old, respectively, at the beginning of the 40-week studies. At the end of the 40-week studies, blood samples were collected from the retroorbital sinus of five male and five female vehicle control mice per strain. The sera were analyzed for antibody titers to rodent viruses (Boorman et al., 1986; Rao et al., 1989a,b). All results were negative.

### Animal Maintenance

Mice were housed individually. Feed and water were available ad libitum. Cages and racks were rotated every other week during the 40-week studies. Further details of animal maintenance are given in Table 1.

### Clinical Examinations and Pathology

All animals were observed twice daily. Clinical findings were recorded daily during the 2-week studies and weekly during the 40-week studies. Clinical findings were recorded postdosing. Body weights were recorded initially, weekly, and at the end of the studies.

Necropsies and microscopic examinations were performed on all mice except positive controls. The heart, right kidney, liver, lung, right testis, and thymus were weighed. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. Tissues examined microscopically are listed in Table 1.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. Upon completion of the laboratory pathologists’ histopathologic evaluations, the slides, paraffin blocks, and residual wet tissues were sent to the NTP Archives for inventory, slide/block match, and wet tissue audit. The slides, individual animal data records, and pathology tables were evaluated by an independent quality assessment laboratory; few discrepancies were identified. The NTP pathologist reviewed the lesions, and consensus diagnosis was achieved among the original pathologist, the quality assurance pathologist, and the NTP pathologist for all neoplastic and skin lesions. Details of these review procedures have been described, in part, by Maronpot and Boorman (1982) and Boorman et al. (1985).

TABLE 1 Experimental Design and Materials and Methods in the Dermal and Gavage Studies of Allyl Bromide

2-Week Dermal Study | 2-Week Gavage Study | 40-Week Gavage Studies
Study Laboratory
BioReliance (Rockville, MD) | BioReliance (Rockville, MD) | BioReliance (Rockville, MD)
Strain and Species
FVB/N mice | C57BL/6 mice | FVB/N mice; C57BL/6 mice; FVB/N-TgN(v-Ha-ras)(Tg.AC) hemizygous mice; B6.129-Trp53^tm1Brd^ (N5) haploinsufficient mice
Animal Source
Taconic Farms, Inc. (Germantown, NY) | Taconic Farms, Inc. (Germantown, NY) | Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
14 days | 15 days | FVB/N and Tg.AC mice: 11-12 days; C57BL/6 and p53 mice: 21 days
Average Age When Studies Began
7 weeks | 8 weeks | FVB/N: 7 weeks; Tg.AC: 6 weeks; C57BL/6 and p53 mice: 9 weeks
Date of First Dose
September 15, 1998 | September 16, 1998 | FVB/N and Tg.AC mice: March 22, 1999; C57BL/6 and p53 mice: April 1, 1999
Duration of Dosing
16 days | 16 days | 40 weeks
Date of Last Dose
September 30, 1998 | October 1, 1998 | FVB/N mice: December 22, 1999; C57BL/6 mice: January 4, 2000; Tg.AC mice: December 21, 1999; p53 mice: January 3, 2000
Necropsy Dates
October 1, 1998 | October 2, 1998 | FVB/N mice: December 23, 1999; C57BL/6 mice: January 5, 2000; Tg.AC mice: December 21-22, 1999; p53 mice: December 30, 1999-January 4, 2000
Average Age at Necropsy
10 weeks | 10 weeks | FVB/N mice: 47 weeks; Tg.AC mice: 45 weeks; C57BL/6 mice: 49 weeks; p53 mice: 48-49 weeks
Size of Study Groups
5 males and 5 females | 5 males and 5 females | 15 males and 15 females
Animals per Cage
1 | 1 | 1
Method of Animal Identification
Tail tattoo | Tail tattoo | Tail tattoo
Diet
Irradiated NTP-2000 Open Formula Diet/pelleted form (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed weekly | Same as dermal study | Same as dermal study
Water
Tap water (Washington Suburban Sanitary Commission Potomac Plant) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum | Same as dermal study | Same as dermal study
Cages
Polycarbonate (Lab Products, Inc., Seaford, DE), changed weekly | Same as dermal study | Same as dermal study
Bedding
Irradiated heat-treated, Sani-Chip hardwood bedding (P.J. Murphy Forest Products, Montville, NJ), changed weekly | Same as dermal study | Same as dermal study
Cage Filters
Remay 2016 (Snow Filtration, West Chester, OH), changed weekly | Same as dermal study | Same as dermal study except changed every other week
Racks
Stainless Steel (Lab Products, Inc., Seaford, DE), changed weekly | Same as dermal study | Same as dermal study, rotated every other week
Animal Room Environment
Temperature: 72° ± 3° F; Relative humidity: 50% ± 15%; Room fluorescent light: 12 hours/day; Room air changes: 10/hour | Temperature: 72° ± 3° F; Relative humidity: 50% ± 15%; Room fluorescent light: 12 hours/day; Room air changes: 10/hour | Temperature: 72° ± 3° F; Relative humidity: 50% ± 15%; Room fluorescent light: 12 hours/day; Room air changes: 10/hour
Doses
0, 7.5, 15, 30, 60, or 120 mg/kg allyl bromide in acetone at a volume of 3.3 mL/kg body weight 5 days per week | 0, 7.5, 15, 30, 60, or 120 mg/kg allyl bromide in corn oil at a volume of 10 mL/kg body weight, 5 days per week | FVB/N and C57BL/6 mice: 0 or 8 mg/kg allyl bromide in corn oil by gavage at a volume of 10 mL/kg body weight, 5 days per week; Tg.AC and p53 mice: 0, 0.5, 1, 2, 4, or 8 mg/kg allyl bromide in corn oil by gavage at a volume of 10 mL/kg body weight, 5 days per week, or 1.25 μg TPA applied dermally in 100 μL acetone three times/week (Tg.AC positive controls only)
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as dermal study | Same as dermal study
Type and Frequency of Observation
Observed twice daily; animals were weighed initially, day 8, and at the end of the study; clinical findings were recorded daily. | Same as dermal study | Observed twice daily; animals were weighed initially, weekly, and at the end of the studies; clinical findings were recorded weekly.
Method of Sacrifice
CO_2_ asphyxiation | CO_2_ asphyxiation | CO_2_ asphyxiation
Necropsy
Necropsies were performed on all animals. Organs weighed were heart, liver, lungs, right kidney, right testis, and thymus. | Same as dermal study | Necropsies were performed on all animals (except positive controls). Organs weighed were heart, liver, lungs, right kidney, right testis, and thymus.
Histopathology
Histopathology was performed on all animals. In addition to gross lesions and tissue masses, the skin (treated and untreated sites) and stomach (forestomach and glandular) were examined. | Histopathology was performed on all animals. In addition to gross lesions and tissue masses, the stomach (forestomach and glandular) was examined. | Histopathology was performed on all animals (except positive controls). In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, large intestine (cecum, colon, and rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular, mediastinal, and mesenteric), ovary, pituitary gland, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, and uterus.

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier (1958). Animals found dead of other than natural causes or missing were censored from the survival analyses; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s (1972) method for testing two groups for equality and Tarone’s (1975) life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation and Analysis of Lesion Incidences

The incidences of lesions are presented in Appendixes A, B, C, and D as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test (Gart et al., 1979) and the Cochran-Armitage trend test (Armitage, 1971; Gart et al., 1979), procedures based on the overall proportion of affected animals, were used to determine significance.

### Analysis of Continuous Variables

Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett (1955) and Williams (1971, 1972). Average severity values were analyzed for significance with the Mann-Whitney U test (Hollander and Wolfe, 1973).

## Quality Assurance Methods

The 40-week studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations (21 CFR, Part 58). In addition, as records from these studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent quality assurance contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Report.

## Genetic Toxicology

### Salmonella typhimurium Mutagenicity Test Protocol

Testing was performed as reported by Zeiger et al. (1992). Allyl bromide was sent to the laboratory as a coded aliquot from Radian Corporation (Austin, TX). It was incubated with the Salmonella typhimurium tester strains TA98 and TA100 either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague-Dawley rat or Syrian hamster liver) for 20 minutes at 37º C. Top agar supplemented with l-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37° C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and five doses of allyl bromide. The high dose was limited by toxicity. All trials that gave a positive response were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive.

### Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al. (1990) and Witt et al. (2000). At the end of the 40-week studies, peripheral blood samples were obtained from male and female mice from each strain. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 2,000 normochromatic erythrocytes (NCEs) in each of up to 15 mice per group. In addition, the percentage of polychromatic erythrocytes (PCEs) in a population of 1,000 erythrocytes was determined as a measure of bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over dose groups with a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each dosed group and the control group (ILS, 1990). In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single dosed group is less than or equal to 0.025 divided by the number of dosed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials. Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects. Because these studies were not repeated, the results of the single micronucleus trials in these mice were accepted without replication.

### Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple aliquots of a chemical were tested in the same assay and different results were obtained among aliquots and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary tables in the Abstract of this Report present a result that represents a scientific judgment of the overall evidence for activity of the chemical in an assay.