# INTRODUCTION

ALLYL BROMIDE

CAS No. 106-95-6

Chemical Formula: C_3_H_5_Br Molecular Weight: 120.99

Synonyms: AB; 3-bromopropene; 3-bromopropylene; propene; 3-bromo-; 2-propenyl bromide

## Chemical and Physical Properties

Allyl bromide is a colorless to light yellow liquid with an unpleasant pungent odor; the boiling point at 760 mm Hg is 71.3° C; the melting point is −119° C, and the density/specific gravity is 1.398 at 4° C (Merck, 1996). The octanol/water partition coefficient (log P) is given as 1.59 by Lipnik et al. (1987) and 1.79 by Hansch et al. (1995). Allyl bromide is slightly soluble in water and miscible with alcohol, chloroform, ether, carbon disulfide, or carbon tetrachloride (Merck, 1996). The allyl bromide water solubility is 3,835 mg/L at 25° C (Yalkowsky and Dannenfelser, 1992). Allyl bromide may react with water with some release of energy, but not violently (NFPA, 1997). Dangerous fire and explosion hazards occur when allyl bromide is exposed to heat, flame, or oxidizers; it also emits toxic bromide fumes when heated to decomposition (Lewis, 1997).

## Production, Use, and Human Exposure

Allyl bromide is produced by a reaction of hydrogen bromide and allyl alcohol; from a reaction of hydro-bromic acid and allyl alcohol; or from a reaction of tri-phenylphosphite, allyl alcohol, and benzyl bromide (Merck, 1996).

Allyl bromide is used primarily as a starting material/chemical intermediate in organic synthesis and as an intermediate in the manufacture of polymers/resins, synthetic perfumes, pharmaceuticals, agricultural chemicals (Kirino et al., 1980; Kim et al., 1992), and other allyl compounds (Stenger, 1978; Merck, 1996). It has also been described as an insecticidal fumigant used in crop protection (Stenger, 1978; Gosselin et al., 1984). The United States Environmental Protection Agency (2002) reported that the production volume for allyl bromide in 1998 and 2002 was between 10,000 and 500,000 pounds. Nineteen United States suppliers were listed in the Chemical Buyers’ Guide for 2000 [personal communication from V. Fung, National Cancer Institute (NCI)]. Occupational exposure to allyl bromide may occur through dermal contact, inhalation, or ingestion (HSDB, 2003).

Allyl bromide is not known to occur naturally. However, allyl bromide has been identified as a pyrolytic degradation product of brominated polymers (Grassie et al., 1986). Allyl bromide has also been identified as a water and air pollutant. Bauman and Stenstrom (1989) identified allyl bromide as one of a group of halogen compounds in seven sources of wastewater and drinking water. Allyl bromide is a major photolytic degradation product of aqueous 1,2-dibromopropene in the absence and presence of hydrogen peroxide (Milano and Vernet, 1988). The allyl bromide yield was 25% relative to the initial trace amount of 1,2-dibromopropene present as a water contaminant. Allyl bromide was one of 78 toxic, volatile, organic compounds routinely monitored (Dunn et al., 1987). In a Russian study, Zenkevich and Konyukhova (1992) reported that allyl bromide was an ecologically significant contaminant.

## Regulatory Status

Allyl bromide is listed in Section 8b of the U.S. Environmental Protection Agency’s Toxic Substances Control Act Chemical Substances Inventory (USEPA, 2006). The National Fire Protection Association (1997) hazard classification is a grade 3; on short exposure, allyl bromide could cause serious injury, and full protective clothing including self-contained breathing apparatus is recommended. The state of Pennsylvania lists allyl bromide as a hazardous substance and tracks it as a potential workplace hazard (Shafer, 1995). It is regulated by the United States Department of Transportation as a flammable liquid (STN, 1994; Shafer, 1995).

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

Kaye et al. (1972) studied allyl halide metabolism in male rats. After the animals were treated subcutaneously with 0.5 mL allyl bromide, 3-hydroxypropylmercapturic acid and allylmercapturic acid and its sulfoxide were excreted in the urine. According to the authors, these metabolites can be formed by a number of different pathways because allyl halides can undergo reactions at either the double bond or the halide bonding site. Eder et al. (1986) performed metabolism studies on allyl compounds, including allyl bromide, as part of a screening strategy to investigate genotoxic potential. They reported that allylic compounds, which are alkylating agents, are detoxified via substitution reactions with glutathione (GSH) to produce mercapturic acids. In addition, allyl bromide undergoes metabolic transformation to acrolein as a reactive intermediate; however, it does not appear to be metabolized via an epoxide route. The metabolic pathways proposed for allyl bromide are shown schematically in Figure 1.

### Humans

No information on the absorption, distribution, metabolism, or excretion of allyl bromide in humans was found in the literature.

## Toxicity

### Experimental Animals

The oral LD_50_ of allyl bromide in rats is 120 mg/kg; the intraperitoneal LD_50_ in mice is 108 mg/kg (Lewis, 1996). Lipnick et al. (1987) reported an LC_50_ for gold fish of 0.8 mg/mL.

The Hazardous Substance Data Bank (HSDB, 2003) reported a toxicity study of allyl bromide conducted by Shell Oil Company in Wistar rats. In this study, allyl bromide was administered by gavage to 10 male rats per group for 14 days at 15 or 60 mg/kg body weight. Additional groups were exposed to control vehicles (water or arachis oil). At 60 mg/kg, the compound caused gastric irritation and reduced body weight gain.

No other toxicity studies of allyl bromide were reported in the literature.

### Humans

No epidemiological studies or reports of health effects in humans related to exposure to allyl bromide were found in the literature.

## Reproductive Toxicity

In the study reported by the HSDB (2003), Shell Oil Company evaluated testicular toxicity in Wistar rats. Wistar rats were exposed orally to 0, 15, or 60 mg allyl bromide/kg body weight per day for 14 days. On day 15, there were no treatment-related changes in the morphology of the kidney, testes, epididymides, ductuli efferentes, or vasa deferentes or in testes weights.

FIGURE 1 Metabolic Pathways for Allyl Bromide (modified from Eder et al., 1986 and Krause et al., 2002)

## Carcinogenicity

### Experimental Animals

Allyl bromide is structurally related to allyl chloride. In the NCI (1977) bioassay of allyl chloride, the chemical was negative for carcinogenic activity in male and female rats and equivocal in male and female mice. There are no 2-year carcinogenicity studies of allyl bromide.

### Humans

No epidemiological studies of allyl bromide were found in the literature.

## Genetic Toxicity

Allyl bromide is a reactive electrophile and direct-acting alkylating agent, and it has been shown to bind to DNA in in vitro model systems (Eder et al., 1982, 1987; Eder and Zugelder, 1990; Ashby and Paton, 1993). Allyl bromide (100% pure) was reported to be mutagenic in the absence of S9 activation in Salmonella typhimurium strain TA100 under conditions that controlled for volatility (Eder et al., 1980). Lijinsky and Andrews (1980) also reported allyl bromide to be mutagenic in S. typhimurium strain TA100 in the absence of metabolic activation; the addition of S9 reduces the mutagenic activity of allyl bromide.

Schiffmann et al. (1983) reported that allyl bromide induced a dose-dependent increase in unscheduled DNA synthesis (UDS) in HeLa S3 cells. Eder et al. (1980) reported direct correlations among mutagenic potency in S. typhimurium strain TA100 (expressed as revertants/µM), alkylating ability, and activity in the UDS assay with several allyl halides, including allyl bromide. Furthermore, comparison of three allyl halides in the UDS assay gave the following activity levels: allyl iodide > allyl bromide > allyl chloride (Eder et al., 1983). Consistent with other studies, Schiffmann et al. (1983) reported a direct correlation between activity in the UDS assay and mutagenicity in Salmonella for these same three allyl halides. In contrast, allylic compounds with greater UDS activity than allyl bromide but lower mutagenicity include cis- and trans-1,3-dichloropropene, 1-chloro-2-butene, and 2,3-dichloro-1-propene. Thus, the correlation between mutagenicity in Salmonella and activity in the UDS assay is not consistent among all allylic compounds.

Studies of in vitro binding of allyl bromide, allyl methanesulphonate, and allyl chloride to salmon sperm DNA (Eder et al., 1987) indicated that all three allyl compounds bound to DNA yielding the same five allyl substituted nucleic bases: N^2^-allylguanine, O^6^-allylguanine, N^7^-allylguanine, N^3^-allyladenine, and N^6^-allyladenine. The order of potency was allyl methanesulphonate > allyl bromide > allyl chloride. The in vitro binding half-life for allyl bromide was 8.1 hours at 37° C (Eder et al., 1986). In an in vivo DNA binding study in which ^14^C-labeled allyl bromide was administered by gavage to mice, these same five allylated nucleic bases were identified in hydrolysate DNA from different organs indicating direct DNA reactivity for allyl bromide in the whole animal (Eder et al., 1983, 1986). Using isolated rat liver perfused with solutions containing either allyl bromide or allyl chloride, Eder and Zugelder (1990) again demonstrated the in vivo formation of the five adducts described above. The authors suggested that the formation of allyl adducts, especially the promutagenic O^6^-guanine adduct, clearly indicates cancer-initiating potential.

Two allyl bromide structural analogs, allyl chloride and 3-chloro-2-methylpropene, have been tested for mutagenicity by the National Toxicology Program (NTP). Allyl chloride, like allyl bromide, was mutagenic in S. typhimurium strain TA100 in the absence of S9 (unpublished data). 3-Chloro-2-methylpropene (methyl allyl chloride), which was more extensively tested for mutagenicity, produced positive results in a variety of assays. It was mutagenic in S. typhimurium strain TA1537 with S9, but in contrast to allyl bromide and allyl chloride, it was negative in strain TA100, with and without S9 (Haworth et al., 1983; Zeiger et al., 1988). In addition, 3-chloro-2-methylpropene was mutagenic in cultured mammalian cells without S9 (Myhr and Caspary, 1991), and it induced chromosomal aberrations and sister chromatid exchanges in Chinese hamster ovary (CHO) cells in the absence of S9 (Gulati et al., 1989). Positive results were also obtained in a sex-linked recessive lethal mutation assay in Drosophila melanogaster (Foureman et al., 1994). Despite these positive results for induced chromosomal damage and mutagenicity in a number of test systems, 3-chloro-2-methylpropene did not induce micronucleated reticulocytes in bone marrow of male mice treated by intraperitoneal injection with up to 250 mg/kg (Shelby et al., 1993). Thus, none of these allylic compounds, all of which are in vitro mutagens, have been shown to induce effects in vivo.

In rats, the metabolic pathway for allyl bromide and allyl chloride was shown to produce S-carboxyl mercapturic acid, which is the principal metabolite of acrolein; neither compound is metabolized via an epoxide pathway (Eder et al., 1987). The mutagenic activity of acrolein has been well studied and appears to be inconsistently detected among a variety of in vitro assays (NTP, 2006), probably due to its extreme electrophilicity, allowing it to react readily with a variety of nucleophilic compounds (Beauchamp et al., 1985). Acrolein has demonstrated direct DNA alkylation (Henschler and Eder, 1986; Foiles et al., 1990; Eder et al., 1993) and is mutagenic in S. typhimurium strains TA100, TA104, and TA1535 (Hales, 1982; Lutz et al., 1982; Haworth et al., 1983; Marnett et al., 1985; Parent et al., 1996). It also induced sister chromatid exchanges but not chromosomal aberrations in cultured CHO cells (Galloway et al., 1987). Conflicting results have been reported for in vitro mammalian cell mutagenicity assays (Curren et al., 1988). Like allyl bromide, acrolein does not increase the frequency of micronucleated erythrocytes in mice treated with the compound for 3 months. The in vivo metabolism of allyl bromide and allyl chloride likely also involves direct alkylation of GSH, resulting in the formation of nonmutagenic mercapturic acids.

## Background on Genetically Altered Mice

Mutation and/or deletions of tumor suppressor genes or activation of protooncogenes can disrupt cell function and predispose an animal to cancer. In the current studies, two genetically altered mouse models with either a loss of heterozygosity in a critical cancer gene (Trp53) or a gain of oncogene function (Ha ras) were used to determine how these animals would respond to allyl bromide exposure. These mouse models are susceptible to the rapid development of cancer. The Tg.AC hemizygous and p53 haploinsufficient mice are being evaluated by the National Institute of Environmental Health Sciences (NIEHS) and the NTP as models for identifying chemical toxicity and/or chemical carcinogenic processes (Tennant et al., 1996; Pritchard et al., 2003).

### FVB/N-TgN(v-Ha-ras)Led (Tg.AC) Hemizygous Mouse Model

Tg.AC mice are hemizygous for a mutant v-Ha-ras transgene. The Tg.AC mouse (on an FVB/N background) was developed by Leder et al. (1990) by introduction via pronuclear injection of a tripartite transgene composed of the promoter of the mouse embryonic zetaglobin gene, through the v-Ha-ras coding sequence, with point mutation in codons 12 and 59, and a simian virus 40 polyadenylation sequence. Because the inducible zeta-globin promoter drives the expression of a mutated v-Ha-ras oncogene, the Tg.AC mouse is regarded as a genetically initiated model.

The Tg.AC transgenic mouse model has been evaluated as a reporter phenotype (skin papillomas) in response to either genotoxic or nongenotoxic carcinogens, including tumor promoters (Spalding et al., 1993, 1999; Tennant et al., 1999). With the exception of bone marrow, constitutive expression of the transgene cannot be detected in adult tissues. The transgene is transcriptionally silent until activated by certain treatments including full-thickness wounding, ultraviolet irradiation, or exposure to some chemicals (Cannon et al., 1997; Trempus et al., 1998). The Tg.AC hemizygous mouse develops a high incidence of skin papillomas in response to topical application of 12-O-tetradecanoyl-phorbol-13-acetate (TPA), and TPA has been used as a positive control in NIEHS Tg.AC mouse studies (Spalding et al., 1993). TPA has been used as a positive control in NIEHS Tg.AC mouse studies to confirm the mice are responsive to carcinogens because it has been found that the subset of Tg.AC mice may revert and become nonresponsive to a tumor promoter (Honchel et al., 2001). Point mutations in the Ha-ras gene are believed to be early events in the induction of skin papillomas and malignancies. Topical application of carcinogens to the shaved dorsal surface of Tg.AC mice induces epidermal squamous cell papillomas or carcinomas, a reporter phenotype that defines the activity of the chemical. The oral route of administration can also generate tumor responses in the skin of Tg.AC mice and lead to squamous cell papillomas and/or carcinomas of the forestomach. To date, the appearance of either spontaneous or induced tumors has been shown to involve transgene expression. However, the mechanism of response by the Tg.AC model to chemical carcinogens is not yet understood.

In NIEHS studies, mice are exposed beginning at 2 months of age for a total of 6 to 9 months. Cutaneous papillomas at various sites have been reported at 10% and 7% incidence in 33-week-old control male and female Tg.AC mice, respectively (Mahler et al., 1998). Cutaneous papillomas occurring at sites such as the lip, pinnae, prepuce, and vulva suggest a possible relationship to grooming and chronic irritation. Up to 32% of Tg.AC homozygous and heterozygous male or female mice can develop odontogenic tumors as early as 33 weeks (Wright et al., 1995; Mahler et al., 1998). A number of different tumor types occur in untreated Tg.AC hemizygous mice at an incidence of greater than 3% including odontogenic tumors, forestomach papillomas, cutaneous papillomas, alveolar/bronchiolar adenomas, salivary gland duct carcinomas, and erythroleukemia (Mahler et al., 1998). In the FVB mouse (the background strain for the Tg.AC hemizygous mouse), alveolar/bronchiolar neoplasms occur at 14 months of age (Mahler et al., 1996).

The Tg.AC hemizygous mouse model was used in the current report for the studies of allyl bromide because this model has been reported to detect both nongenotoxic and genotoxic carcinogens (Spalding et al., 1993; Tennant et al., 1995, 1996; Pritchard et al., 2003).

### B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient Mouse Model

The heterozygous B6.129-Trp53(N12)^tmlBrd(+/−)^ mouse (on a B6.129S7 background) was developed by Donehower et al. (1992). A null mutation was introduced into one p53 allele by homologous recombination in murine embryonic stem cells. Insertion of a neo cassette resulted in deletion of a 450-base pair gene fragment containing 106 nucleotides of exon 5 and approximately 350 nucleotides of intron 4.

Trp53, a nuclear protein, plays an essential role in the regulation of the cell cycle, specifically in the transition from G_0_ to G_1_, as well as G_2_ to M, and the spindle apparatus. The p53 protein has a short half-life and exists at very low concentration under normal cell physiological conditions. However, in DNA damaged cells that are able to replicate, p53 is expressed in high amounts with a significant increase in half-life due to post-translational modification (phosphorylation or acetylation). Mutation in p53 may also increase the protein half-life and alter the functions that may contribute to transformation and development of the malignant phenotype. p53 is a DNA-binding protein containing DNA-binding, oligomerization, and transcription activation domains. Many amino acid residues in different p53 domains may be phosphorylated or acetylated, which may determine specific p53 functions. It is postulated to bind as a tetramer to a p53-binding site and activate expression of downstream genes that inhibit growth and/or invasion or promote apoptosis, functioning as a tumor suppressor. This protein is critical to tumor suppression in humans and rodents. Mutants of p53 that fail to bind the consensus DNA binding site, and hence are unable to function as tumor suppressors, frequently occur in human cancers. Alterations of the Trp53 gene occur not only as somatic mutations in human malignancies, but also as germline mutations in some cancer-prone families with Li-Fraumeni syndrome.

The mouse heterozygous for a p53 null allele (+/−) has only a single functional wild-type p53 allele, which provides a target for mutagens. The p53 tumor suppressor gene is one of the most common sites for mutations and gene alterations in human cancer (Harris, 1996a,b,c).

Heterozygous p53 mice develop normally and, like humans and other mammals, develop cancer (primarily lymphomas or sarcomas) with age, but often with decreased latency.

## Study Rationale

Allyl bromide was nominated for study by the NCI because there was no existing 2-year carcinogenicity study for the chemical. Transgenic mouse models were used to screen for toxicity and carcinogenicity. The p53 haploinsufficient and Tg.AC hemizygous mouse models were selected for this screen because they were the models under study at the NTP for possible use in chemical hazard identification.