# APPENDIX G CHEMICAL CHARACTERIZATION AND DOSE FORMULATION STUDIES

## Procurement and Characterization

### Allyl Bromide

Allyl bromide was obtained from Fluka Chemical Corporation (Buchs, Switzerland) in one lot (330638) and from Aldrich Chemical Co. in one lot (03614HN). Lot 330638 was used in the 2-week studies and lot 03614HN was used in the 40-week studies. Identity and purity analyses were conducted by the analytical chemistry laboratory, Midwest Research Institute (Kansas City, MO) and the study laboratory, BioReliance (Rockville, MD). Reports on analyses performed in support of the allyl bromide studies are on file at the National Institute of Environmental Health Sciences.

Both lots of allyl bromide, a clear, colorless liquid, were identified by the analytical chemistry laboratory using infrared (IR) and proton nuclear magnetic resonance (NMR) spectroscopy and by the study laboratory using IR spectroscopy. All IR and NMR spectra were consistent with the literature spectra (Aldrich, 1985, 1993) and spectra of a reference standard of the same lot. Representative IR and NMR spectra are presented in Figures G1 and G2.

The purity of each lot was determined by the analytical chemistry laboratory using gas chromatography (GC) by system A and by the study laboratory using GC by system B (Table G1). For lot 330638, GC by system A indicated one major peak and five impurities with a combined peak area of 0.7% relative to the total peak area. GC by system B indicated one major peak and three impurities with a combined peak area of less than 0.5%. The relative purity was 102% when compared to a reference standard from the same lot. The overall purity of lot 330638 was greater than 99%. For lot 03614HN, GC by system A indicated one major peak and four impurities with a combined peak area of 0.45% relative to the total peak area. GC by system B indicated one major peak and three impurities with a total combined area less than 0.3% of the total peak area. The relative purity was 102% when compared to a reference standard from the same lot. The overall purity of lot 03614HN was greater than 99%.

During the 40-week studies, additional purity analyses were performed by the study laboratory at 26 weeks and at the end of the study using GC by system B. To ensure stability, the bulk chemical was stored in a sealed container under a nitrogen headspace, protected from light, at 2° to 8° C. No degradation of the bulk chemical was detected.

### Acetone

ACS-grade acetone was obtained from Fisher Scientific (Hampton, NH) in two lots (963514 and 982335) that were used as the vehicle in the 2-week dermal study. The study laboratory determined the identity using IR spectroscopy and the purity using GC by system C (Table G1). IR spectra were consistent with a literature spectrum (Aldrich, 1981). GC indicated a major peak; two impurities of 0.15% and 0.05% of the total peak area; several minor impurities, each less than 0.01% of the total peak area; and an overall purity greater than 99.7%.

### Corn Oil

Corn oil in multiple lots was used as the vehicle during the 2-week and 40-week gavage studies. The study laboratory analyzed peroxide levels prior to use and monthly during the study using potentiometric titration; all peroxide concentrations were less than 3 mEq/kg.

## Preparation and Analysis of Dose Formulations

For the 2-week dermal study, the dose formulations were prepared once by pipetting the appropriate amounts of allyl bromide and acetone into a volumetric flask and mixing thoroughly (Table G2). The dose formulations were stored in amber glass vials under a headspace of inert gas, protected from light, at 2° to 8° C for up to 35 days.

Prior to the 2-week dermal study, the analytical chemistry laboratory conducted stability studies on 1 mg/mL formulations of allyl bromide in acetone using GC by system D (Table G1). Formulations were stored in glass vials capped with Teflon^®^-lined septa, protected from light, at 25° and 5° C, and at simulated animal room conditions. Stability was confirmed for up to 35 days at 25° and 5° C and up to 3 hours at animal room conditions.

For the 2-week and 40-week gavage studies, the appropriate amounts of allyl bromide and corn oil were pipetted into a volumetric flask and mixed thoroughly (Table G2). Dose formulations were prepared once for the 2-week study and every 2 weeks during the 40-week studies. Dose formulations were stored in amber glass vials with Teflon^®^-lined septa and aluminum crimp caps under a headspace of inert gas, protected from light, at 2° to 8° C for up to 21 days, with the exception of formulations used between November 16, 1999, and December 20, 1999, which were stored for 27 days. Dose formulations prepared on December 7, 1999, stored at 2° to 8° C for 28 days, then at −20° C until analyzed on January 13, 2000, confirmed stability for up to 28 days.

A solubility study of allyl bromide in corn oil was conducted at the analytical chemistry laboratory using GC by a system similar to system A; the maximum solubility was 142.2 mg/mL. No homogeneity studies were conducted on dose formulations in corn oil as concentrations used in the 2-week study (0.75 to 12.0 mg/mL) and 40-week studies (0.05 to 0.80 mg/mL) were well below the maximum solubility.

For the 2-week and 40-week gavage studies, the analytical chemistry laboratory conducted stability studies on 0.37 mg/mL formulations of allyl bromide in corn oil using GC by system E (Table G1). Formulations were stored in amber glass vials capped with Teflon^®^-lined septa, protected from light, at 25° and 5° C, and at simulated animal room conditions. Stability was confirmed for up to 16 days at 25° C, up to 21 days at 5° C, and up to 3 hours at animal room conditions. Later, a second stability study was conducted by the analytical chemistry laboratory on 0.74 mg/mL formulations under the same conditions as those previously described. No significant trend toward loss was observed at 25° or 5° C up to 42 days, though variability was large (RSD 10.8%), and no significant loss was observed at animal room conditions up to 3 hours.

Periodic analyses of the dose formulations were conducted by the study laboratory using GC by a system similar to system D (dermal) or a system similar to system E (gavage). For the 2-week dermal and gavage studies, the dose formulations were analyzed once. Animal room samples were also analyzed. Of the dose formulations used and analyzed for the dermal study, all five were within 10% of the target concentrations; all five animal room samples were within 10% of the target concentrations (Table G4). Of the dose formulations used and analyzed for the 2-week gavage study, all five were within 10% of the target concentrations; one of five animal room samples was within 10% of the target concentrations (Table G5). For the 40-week gavage studies, formulations were analyzed at least every 12 weeks; animal room samples were also analyzed. Of the dose formulations used and analyzed, all 25 were within 10% of the target concentrations; 17 of 30 animal room samples were within 10% of the target concentrations (Table G3). Increased awareness of volatility issues and subsequent careful handling improved animal room sample results over the course of the 40-week studies.

FIGURE G1 Infrared Absorption Spectrum of Allyl Bromide

FIGURE G2 Proton Nuclear Magnetic Resonance Spectrum of Allyl Bromide

TABLE G1 Gas Chromatography Systems Used in the Studies of Allyl Bromide^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization | DB-1, 30 m × 0.53 mm, 1.5-μm film thickness, (J&W Scientific, Folsom, CA) | Helium at 10 mL/minute | 40° C held for 5 minutes, then to 250° C at 10° C/minute, held for 4 minutes
System B
Flame ionization | DB-1, 30 m × 0.53 mm, 1.5-μm film thickness, (J&W Scientific) | Nitrogen at 20-23.3 mL/minute | 40° C held for 5 minutes, then to 90° C at 10° C/minute
System C
Flame ionization | DB-1, 30 m × 0.53 mm, 3-μm film thickness (J&W Scientific) | Nitrogen at 17.5 mL/minute and 25 psi | 40° C held 4 minutes, then 170° C at 10° C/minute, held 1 minute
System D
Electron capture | Rtx-1, 30 m × 0.53 mm, 3-μm film thickness (Restek, Bellafonte, PA) | | 40° C held 14 minutes, then 160° C at 40° C/minute, held 3 minutes
System E
Flame ionization | Rtx-1, 30 m × 0.53 mm, 3-μm film thickness (Restek) | Helium at 10 mL/minute | 40° C held 5 minutes, then 250° C at 50° C/minute, held 5 minutes

a Gas chromatographs were manufactured by Varian (Palo Alto, CA) (Systems A, D, and E) or Hewlett Packard (Palo Alto, CA) (Systems B and C)

TABLE G2 Preparation and Storage of Dose Formulations in the Dermal and Gavage Studies of Allyl Bromide

Dermal Study | Gavage Studies
Preparation
The required amounts of allyl bromide and ACS-grade acetone were pipetted into a volumetric flask and mixed thoroughly. Dose formulations were prepared once. | The required amount of allyl bromide was added to corn oil in a volumetric flask and mixed thoroughly. Dose formulations were prepared once every 2 weeks.
Chemical Lot Number
330638 | 03614HN and 330638
Maximum Storage Time
35 days | 21 days^a^
Storage Conditions
Formulations were transferred to 5-mL amber glass vials, sealed under a nitrogen headspace, and refrigerated at 2° to 8° C. | Stored in sealed amber glass vials under a headspace of inert gas, protected from light, at 2° to 8° C.
Study Laboratory
BioReliance; (Rockville, MD) | BioReliance; (Rockville, MD)

a Dose formulations used between November 16, 1999, and December 20, 1999, were stored for 27 days. A subsequent stability study on formulations prepared December 7, 1999, stored at 2° to 8° C for 28 days, then at −20° C until analyzed, confirmed stability for 28 days; all formulations were within 10% of target concentrations (Table G3).

TABLE G3 Results of Analyses of Dose Formulations Administered to FVB/N, C57BL/6, Tg.AC Hemizygous, and p53 Haploinsufficient Mice in the 40-Week Gavage Study of Allyl Bromide

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
March 16, 1999 | March 16, 1999 | 0.05 | 0.0455 | −9
March 16, 1999 | March 16, 1999 | 0.10 | 0.0953 | −5
March 16, 1999 | March 16, 1999 | 0.20 | 0.188 | −6
March 16, 1999 | March 16, 1999 | 0.40 | 0.415 | +4
March 16, 1999 | March 16, 1999 | 0.80 | 0.826 | +3
March 16, 1999 | April 14, 1999^b^ | 0.05 | 0.0332 | −34
March 16, 1999 | April 14, 1999^b^ | 0.10 | 0.0541 | −46
March 16, 1999 | April 14, 1999^b^ | 0.20 | 0.103 | −49
March 16, 1999 | April 14, 1999^b^ | 0.40 | 0.286 | −29
March 16, 1999 | April 14, 1999^b^ | 0.80 | 0.607 | −24
May 11, 1999 | May 11, 1999 | 0.05 | 0.0475 | −5
May 11, 1999 | May 11, 1999 | 0.10 | 0.0959 | −4
May 11, 1999 | May 11, 1999 | 0.20 | 0.187 | −7
May 11, 1999 | May 11, 1999 | 0.40 | 0.413 | +3
May 11, 1999 | May 11, 1999 | 0.80 | 0.756 | −6
May 11, 1999 | June 3, 1999^b^ | 0.05 | 0.0289 | −42
May 11, 1999 | June 3, 1999^b^ | 0.10 | 0.0489 | −51
May 11, 1999 | June 3, 1999^b^ | 0.20 | 0.116 | −42
May 11, 1999 | June 3, 1999^b^ | 0.40 | 0.193 | −52
May 11, 1999 | June 3, 1999^b^ | 0.80 | 0.354 | −56
August 3, 1999 | August 3, 1999 | 0.05 | 0.0462 | −8
August 3, 1999 | August 3, 1999 | 0.10 | 0.0920 | −8
August 3, 1999 | August 3, 1999 | 0.20 | 0.183 | −9
August 3, 1999 | August 3, 1999 | 0.40 | 0.374 | −7
August 3, 1999 | August 3, 1999 | 0.80 | 0.741 | −7
August 3, 1999 | August 24, 1999^b^ | 0.05 | 0.0450 | −10
August 3, 1999 | August 24, 1999^b^ | 0.10 | 0.0692 | −31
August 3, 1999 | August 24, 1999^b^ | 0.20 | 0.196 | −2
August 3, 1999 | August 24, 1999^b^ | 0.40 | 0.304 | −24
August 3, 1999 | August 24, 1999^b^ | 0.80 | 0.784 | −2
September 28, 1999 | September 28, 1999 | 0.05 | 0.0525 | +5
September 28, 1999 | September 28, 1999 | 0.10 | 0.100 | 0
September 28, 1999 | September 28, 1999 | 0.20 | 0.190 | −5
September 28, 1999 | September 28, 1999 | 0.40 | 0.379 | −5
September 28, 1999 | September 28, 1999 | 0.80 | 0.731 | −9
September 28, 1999 | October 22, 1999^b^ | 0.05 | 0.0476 | −5
September 28, 1999 | October 22, 1999^b^ | 0.10 | 0.0912 | −9
September 28, 1999 | October 22, 1999^b^ | 0.20 | 0.198 | −1
September 28, 1999 | October 22, 1999^b^ | 0.40 | 0.359 | −10
September 28, 1999 | October 22, 1999^b^ | 0.80 | 0.775 | −3
December 7, 1999 | January 13, 2000^c^ | 0.05 | 0.0527 | +5
December 7, 1999 | January 13, 2000^c^ | 0.10 | 0.0916 | −8
December 7, 1999 | January 13, 2000^c^ | 0.20 | 0.187 | −7
December 7, 1999 | January 13, 2000^c^ | 0.40 | 0.407 | +2
December 7, 1999 | January 13, 2000^c^ | 0.80 | 0.763 | −5
December 7, 1999 | January 13, 2000^b^ | 0.05 | 0.0481 | −4
December 7, 1999 | January 13, 2000^b^ | 0.10 | 0.0733 | −27
December 7, 1999 | January 13, 2000^b^ | 0.20 | 0.195 | −3
December 7, 1999 | January 13, 2000^b^ | 0.40 | 0.400 | 0
December 7, 1999 | January 13, 2000^b^ | 0.80 | 0.759 | −5
December 21, 1999 | December 21, 1999 | 0.05 | 0.0550 | +10
December 21, 1999 | December 21, 1999 | 0.10 | 0.109 | +9
December 21, 1999 | December 21, 1999 | 0.20 | 0.218 | +9
December 21, 1999 | December 21, 1999 | 0.40 | 0.437 | +9
December 21, 1999 | December 21, 1999 | 0.80 | 0.854 | +7
December 21, 1999 | January 13, 2000^b^ | 0.05 | 0.0548 | +10
December 21, 1999 | January 13, 2000^b^ | 0.10 | 0.108 | +8
December 21, 1999 | January 13, 2000^b^ | 0.20 | 0.198 | −1
December 21, 1999 | January 13, 2000^b^ | 0.40 | 0.404 | +1
December 21, 1999 | January 13, 2000^b^ | 0.80 | 0.814 | +2

a Results of duplicate analyses. Dosing volume=10 mL/kg; 0.05 mg/mL=0.5 mg/kg, 0.10 mg/mL=1.0 mg/kg, 0.20 mg/mL=2 mg/kg, 0.40 mg/mL=4 mg/kg, 0.80 mg/mL=8 mg/kg

b Animal room samples

c Used in study but not analyzed at the time of preparation; samples refrigerated until analysis

TABLE G4 Results of Analyses of Dose Formulations Administered to FVB/N Mice in the 2-Week Dermal Study of Allyl Bromide

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
September 9, 1998 | September 10, 1998 | 2.27 | 2.39 | +5
September 9, 1998 | September 10, 1998 | 4.55 | 4.73 | +4
September 9, 1998 | September 10, 1998 | 9.09 | 8.96 | −1
September 9, 1998 | September 10, 1998 | 18.2 | 18.40 | +1
September 9, 1998 | September 10, 1998 | 36.4 | 36.90 | +1
September 9, 1998 | October 2, 1998^b^ | 2.27 | 2.13 | −6
September 9, 1998 | October 2, 1998^b^ | 4.55 | 4.39 | −3
September 9, 1998 | October 2, 1998^b^ | 9.09 | 8.64 | −5
September 9, 1998 | October 2, 1998^b^ | 18.2 | 17.9 | −2
September 9, 1998 | October 2, 1998^b^ | 36.4 | 34.5 | −5

a Results of duplicate analyses. Dosing volume=3.3 mL/kg; 2.27 mg/mL=7.5 mg/kg, 4.55 mg/mL=15 mg/kg, 9.09 mg/mL=30 mg/kg, 18.2 mg/mL=60 mg/kg, 36.4 mg/mL=120 mg/kg

b Animal room samples

TABLE G5 Results of Analyses of Dose Formulations Administered to C57BL/6 Mice in the 2-Week Gavage Study of Allyl Bromide

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
September 10, 1998 | September 11, 1998 | 0.75 | 0.77 | +3
September 10, 1998 | September 11, 1998 | 1.5 | 1.56 | +4
September 10, 1998 | September 11, 1998 | 3.0 | 3.02 | +1
September 10, 1998 | September 11, 1998 | 6.0 | 6.09 | +2
September 10, 1998 | September 11, 1998 | 12.0 | 12.8 | +7
September 10, 1998 | October 5, 1998^b^ | 0.75 | 0.493 | −34
September 10, 1998 | October 5, 1998^b^ | 1.5 | 1.05 | −30
September 10, 1998 | October 5, 1998^b^ | 3.0 | 2.52 | −16
September 10, 1998 | October 5, 1998^b^ | 6.0 | 5.02 | −16
September 10, 1998 | October 5, 1998^b^ | 12.0 | 11.4 | −5

a Results of duplicate analyses. Dosing volume=10 mL/kg; 0.75 mg/mL=7.5 mg/kg, 1.5 mg/mL=15 mg/kg, 3.0 mg/mL=30 mg/kg, 6.0 mg/mL=60 mg/kg, 12.0 mg/mL=120 mg/kg

b Animal room samples