# APPENDIX F ORGAN WEIGHTS AND ORGAN-WEIGHT-TO-BODY-WEIGHT RATIOS

TABLE F1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for FVB/N Mice in the 2-Week Dermal Study of Allyl Bromide^a^

| Vehicle Control | 7.5 mg/kg | 15 mg/kg | 30 mg/kg | 60 mg/kg | 120 mg/kg
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Necropsy body wt. | 27.1 ± 0.9 | 27.2 ± 0.9 | 27.0 ± 0.2 | 27.2 ± 0.4 | 27.6 ± 0.5 | 27.5 ± 0.9
Heart
Absolute | 0.133 ± 0.005 | 0.131 ± 0.005 | 0.137 ± 0.003 | 0.136 ± 0.004 | 0.137 ± 0.005 | 0.140 ± 0.005
Relative | 4.918 ± 0.097 | 4.808 ± 0.115 | 5.059 ± 0.101 | 4.989 ± 0.094 | 4.982 ± 0.203 | 5.099 ± 0.146
R. Kidney
Absolute | 0.263 ± 0.011 | 0.271 ± 0.019 | 0.271 ± 0.009 | 0.280 ± 0.011 | 0.277 ± 0.006 | 0.277 ± 0.010
Relative | 9.695 ± 0.240 | 9.924 ± 0.408 | 10.049 ± 0.287 | 10.283 ± 0.289 | 10.041 ± 0.181 | 10.071 ± 0.301
Liver
Absolute | 1.620 ± 0.058 | 1.568 ± 0.089 | 1.545 ± 0.040 | 1.623 ± 0.064 | 1.660 ± 0.018 | 1.724 ± 0.054
Relative | 59.711 ± 0.648 | 57.619 ± 2.141 | 57.237 ± 1.639 | 59.614 ± 1.669 | 60.150 ± 0.771 | 62.678 ± 1.194
Lung
Absolute | 0.159 ± 0.008 | 0.162 ± 0.009 | 0.163 ± 0.001 | 0.169 ± 0.004 | 0.185 ± 0.010 | 0.175 ± 0.012
Relative | 5.862 ± 0.137 | 5.962 ± 0.177 | 6.040 ± 0.092 | 6.220 ± 0.130 | 6.714 ± 0.418 | 6.324 ± 0.239
R. Testis
Absolute | 0.087 ± 0.002 | 0.089 ± 0.003 | 0.089 ± 0.003 | 0.084 ± 0.002 | 0.089 ± 0.001 | 0.086 ± 0.002
Relative | 3.223 ± 0.138 | 3.300 ± 0.121 | 3.302 ± 0.097 | 3.092 ± 0.103 | 3.237 ± 0.102 | 3.140 ± 0.100
Thymus
Absolute | 0.042 ± 0.002 | 0.041 ± 0.003 | 0.038 ± 0.002 | 0.043 ± 0.005 | 0.047 ± 0.003 | 0.046 ± 0.002
Relative | 1.561 ± 0.121 | 1.524 ± 0.088 | 1.409 ± 0.084 | 1.590 ± 0.182 | 1.700 ± 0.077 | 1.690 ± 0.116
Female
Necropsy body wt. | 21.5 ± 0.5 | 21.9 ± 0.5 | 20.9 ± 0.4 | 21.3 ± 0.4 | 21.8 ± 0.3 | 21.8 ± 0.5
Heart
Absolute | 0.121 ± 0.003 | 0.121 ± 0.002 | 0.116 ± 0.002 | 0.121 ± 0.004 | 0.118 ± 0.003 | 0.122 ± 0.004
Relative | 5.620 ± 0.088 | 5.557 ± 0.138 | 5.577 ± 0.137 | 5.691 ± 0.152 | 5.419 ± 0.152 | 5.608 ± 0.114
R. Kidney
Absolute | 0.177 ± 0.005 | 0.186 ± 0.006 | 0.170 ± 0.005 | 0.170 ± 0.004 | 0.174 ± 0.003 | 0.177 ± 0.008
Relative | 8.225 ± 0.142 | 8.522 ± 0.219 | 8.139 ± 0.323 | 7.971 ± 0.266 | 8.001 ± 0.139 | 8.120 ± 0.337
Liver
Absolute | 1.269 ± 0.033 | 1.377 ± 0.050 | 1.251 ± 0.028 | 1.253 ± 0.030 | 1.259 ± 0.038 | 1.313 ± 0.063
Relative | 58.888 ± 0.360 | 62.903 ± 1.298 | 59.923 ± 1.761 | 58.710 ± 1.033 | 57.789 ± 1.658 | 60.227 ± 2.085
Lung
Absolute | 0.156 ± 0.003 | 0.162 ± 0.008 | 0.155 ± 0.005 | 0.154 ± 0.006 | 0.151 ± 0.008 | 0.163 ± 0.004
Relative | 7.230 ± 0.132 | 7.405 ± 0.360 | 7.404 ± 0.274 | 7.218 ± 0.276 | 6.948 ± 0.335 | 7.486 ± 0.185
Thymus
Absolute | 0.049 ± 0.005 | 0.053 ± 0.005 | 0.052 ± 0.002 | 0.051 ± 0.006 | 0.044 ± 0.006 | 0.058 ± 0.003
Relative | 2.268 ± 0.223 | 2.427 ± 0.172 | 2.475 ± 0.101 | 2.421 ± 0.302 | 2.035 ± 0.292 | 2.691 ± 0.182

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). Differences from the vehicle control group are not significant by Dunnett’s test.

TABLE F2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for FVB/N Mice in the 40-Week Gavage Study of Allyl Bromide^a^

| Vehicle Control | 8 mg/kg
n | 15 | 14
Male
Necropsy body wt. | 42.2 ± 1.0 | 41.8 ± 0.9
Heart
Absolute | 0.189 ± 0.003 | 0.185 ± 0.002
Relative | 4.500 ± 0.113 | 4.449 ± 0.086
R. Kidney
Absolute | 0.353 ± 0.006 | 0.340 ± 0.007
Relative | 8.421 ± 0.216 | 8.164 ± 0.206
Liver
Absolute | 1.914 ± 0.041 | 1.922 ± 0.059
Relative | 45.503 ± 0.913 | 45.896 ± 0.706
Lung
Absolute | 0.219 ± 0.004^b^ | 0.239 ± 0.009
Relative | 5.188 ± 0.173^b^ | 5.777 ± 0.297
R. Testis
Absolute | 0.090 ± 0.003 | 0.093 ± 0.001^b^
Relative | 2.158 ± 0.098 | 2.255 ± 0.062^b^
Thymus
Absolute | 0.034 ± 0.004 | 0.030 ± 0.003
Relative | 0.798 ± 0.077 | 0.700 ± 0.062
Female
Necropsy body wt. | 32.3 ± 1.4 | 32.6 ± 0.9
Heart
Absolute | 0.138 ± 0.003 | 0.142 ± 0.004
Relative | 4.355 ± 0.133 | 4.353 ± 0.095
R. Kidney
Absolute | 0.202 ± 0.006 | 0.215 ± 0.004
Relative | 6.334 ± 0.187 | 6.633 ± 0.194
Liver
Absolute | 1.547 ± 0.046 | 1.550 ± 0.033
Relative | 48.439 ± 1.105 | 47.693 ± 0.749
Lung
Absolute | 0.213 ± 0.006 | 0.210 ± 0.008
Relative | 6.779 ± 0.353 | 6.441 ± 0.176
Thymus
Absolute | 0.029 ± 0.002 | 0.027 ± 0.002^b^
Relative | 0.910 ± 0.063 | 0.823 ± 0.060^b^

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). Differences from the vehicle control group are not significant by Dunnett’s test.

b n=13

TABLE F3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Tg.AC Hemizygous Mice in the 40-Week Gavage Study of Allyl Bromide^a^

| Vehicle Control | 0.5 mg/kg | 1 mg/kg | 2 mg/kg | 4 mg/kg | 8 mg/kg
Male
n | 12 | 9 | 9 | 12 | 6 | 11
Necropsy body wt | 39.2 ± 1.5 | 36.5 ± 1.1 | 39.7 ± 1.4 | 36.9 ± 1.5 | 37.6 ± 1.5 | 38.3 ± 1.2
Heart
Absolute | 0.185 ± 0.005 | 0.175 ± 0.003 | 0.185 ± 0.007 | 0.182 ± 0.006 | 0.178 ± 0.006 | 0.184 ± 0.006
Relative | 4.761 ± 0.163 | 4.801 ± 0.112 | 4.698 ± 0.198 | 4.976 ± 0.139 | 4.748 ± 0.092 | 4.806 ± 0.088
R. Kidney
Absolute | 0.337 ± 0.010 | 0.320 ± 0.014 | 0.324 ± 0.009 | 0.321 ± 0.010 | 0.342 ± 0.015 | 0.335 ± 0.010
Relative | 8.660 ± 0.269 | 8.760 ± 0.275 | 8.174 ± 0.178 | 8.753 ± 0.171 | 9.158 ± 0.440 | 8.775 ± 0.167
Liver
Absolute | 1.946 ± 0.080 | 1.693 ± 0.056 | 1.894 ± 0.072 | 1.726 ± 0.069 | 1.855 ± 0.066 | 1.819 ± 0.065
Relative | 49.659 ± 0.632 | 46.486 ± 1.390 | 47.786 ± 1.440 | 46.858 ± 0.673 | 49.542 ± 1.674 | 47.510 ± 0.702
Lung
Absolute | 0.251 ± 0.009 | 0.265 ± 0.026 | 0.324 ± 0.025^*^ | 0.247 ± 0.014 | 0.248 ± 0.011^b^ | 0.243 ± 0.012
Relative | 6.462 ± 0.260 | 7.350 ± 0.810 | 8.163 ± 0.591^*^ | 6.737 ± 0.361 | 6.806 ± 0.526^b^ | 6.382 ± 0.344
R. Testis
Absolute | 0.086 ± 0.003 | 0.087 ± 0.003 | 0.075 ± 0.004^*^ | 0.083 ± 0.004 | 0.094 ± 0.002 | 0.088 ± 0.001
Relative | 2.218 ± 0.084 | 2.374 ± 0.048 | 1.911 ± 0.122 | 2.256 ± 0.115 | 2.518 ± 0.124 | 2.315 ± 0.075
Thymus
Absolute | 0.023 ± 0.003 | 0.016 ± 0.002 | 0.024 ± 0.002 | 0.021 ± 0.003 | 0.020 ± 0.003 | 0.023 ± 0.002
Relative | 0.562 ± 0.057 | 0.443 ± 0.052 | 0.598 ± 0.059 | 0.556 ± 0.068 | 0.533 ± 0.083 | 0.600 ± 0.043
Female
n | 9 | 10 | 8 | 8 | 11 | 12
Necropsy body wt | 30.2 ± 0.6 | 31.5 ± 2.5 | 29.7 ± 1.9 | 31.5 ± 1.6 | 30.1 ± 0.8 | 31.7 ± 1.3
Heart
Absolute | 0.150 ± 0.009 | 0.130 ± 0.006 | 0.130 ± 0.004 | 0.142 ± 0.006 | 0.146 ± 0.005 | 0.139 ± 0.004
Relative | 4.947 ± 0.236 | 4.260 ± 0.185 | 4.446 ± 0.186 | 4.553 ± 0.236 | 4.863 ± 0.180 | 4.439 ± 0.136
R. Kidney
Absolute | 0.209 ± 0.004^c^ | 0.209 ± 0.012 | 0.207 ± 0.008 | 0.206 ± 0.006 | 0.216 ± 0.008 | 0.207 ± 0.005
Relative | 7.023 ± 0.171^c^ | 6.808 ± 0.360 | 7.137 ± 0.441 | 6.645 ± 0.329 | 7.242 ± 0.322 | 6.597 ± 0.184
Liver
Absolute | 1.735 ± 0.126 | 1.475 ± 0.111 | 1.501 ± 0.032 | 1.604 ± 0.077 | 1.530 ± 0.045^d^ | 1.556 ± 0.059
Relative | 57.291 ± 3.517 | 47.039 ± 0.806^**^ | 51.634 ± 2.405 | 51.127 ± 1.621 | 50.741 ± 1.170^d^ | 49.146 ± 0.627^**^
Lung
Absolute | 0.244 ± 0.014 | 0.196 ± 0.007^*^ | 0.226 ± 0.011 | 0.295 ± 0.022^*^ | 0.212 ± 0.008^d^ | 0.251 ± 0.011
Relative | 8.097 ± 0.493 | 6.517 ± 0.429 | 7.817 ± 0.627 | 9.596 ± 0.974 | 7.012 ± 0.216^d^ | 7.981 ± 0.374
Thymus
Absolute | 0.024 ± 0.001 | 0.030 ± 0.004 | 0.023 ± 0.003 | 0.025 ± 0.003 | 0.025 ± 0.002 | 0.032 ± 0.002
Relative | 0.787 ± 0.054 | 0.920 ± 0.067 | 0.774 ± 0.059 | 0.793 ± 0.078 | 0.834 ± 0.062 | 1.004 ± 0.046

* Significantly different (P≤0.05) from the vehicle control group by Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

b n=5

c n=8

d n=10

TABLE F4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for C57BL/6 Mice in the 2-Week Gavage Study of Allyl Bromide^a^

| Vehicle Control | 7.5 mg/kg | 15 mg/kg | 30 mg/kg | 60 mg/kg | 120 mg/kg
Male
n | 5 | 5 | 5 | 5 | 5 | 2
Necropsy body wt. | 22.2 ± 0.9 | 23.1 ± 0.6 | 23.2 ± 1.0 | 23.5 ± 0.9 | 23.1 ± 0.8 | 22.2 ± 0.4
Heart
Absolute | 0.109 ± 0.003 | 0.114 ± 0.004 | 0.111 ± 0.003 | 0.113 ± 0.004 | 0.111 ± 0.003 | 0.108 ± 0.005
Relative | 4.920 ± 0.076 | 4.938 ± 0.204 | 4.803 ± 0.087 | 4.843 ± 0.218 | 4.797 ± 0.104 | 4.881 ± 0.303
R. Kidney
Absolute | 0.171 ± 0.004 | 0.186 ± 0.002 | 0.185 ± 0.003 | 0.179 ± 0.008 | 0.178 ± 0.009 | 0.189 ± 0.011
Relative | 7.723 ± 0.218 | 8.071 ± 0.213 | 8.058 ± 0.341 | 7.620 ± 0.193 | 7.711 ± 0.178 | 8.520 ± 0.609
Liver
Absolute | 1.177 ± 0.088 | 1.313 ± 0.031 | 1.326 ± 0.033 | 1.413 ± 0.063^**^ | 1.455 ± 0.036^**^,^b^ | 1.313^c^
Relative | 52.764 ± 2.233 | 56.928 ± 1.533 | 57.447 ± 1.219 | 60.144 ± 1.554^**^ | 60.405 ± 0.696^**^,^b^ | 58.356^c^
Lung
Absolute | 0.151 ± 0.008 | 0.162 ± 0.004 | 0.156 ± 0.008 | 0.172 ± 0.013 | 0.154 ± 0.005 | 0.158 ± 0.009
Relative | 6.816 ± 0.374 | 7.028 ± 0.317 | 6.749 ± 0.133 | 7.358 ± 0.607 | 6.691 ± 0.218 | 7.118 ± 0.496
R. Testis
Absolute | 0.087 ± 0.003 | 0.077 ± 0.007 | 0.074 ± 0.005 | 0.075 ± 0.005 | 0.067 ± 0.003^*^ | 0.081 ± 0.011
Relative | 3.904 ± 0.044 | 3.341 ± 0.264 | 3.180 ± 0.133^*^ | 3.204 ± 0.128^*^ | 2.925 ± 0.125^**^ | 3.628 ± 0.417
Thymus
Absolute | 0.047 ± 0.003 | 0.043 ± 0.005 | 0.046 ± 0.004 | 0.049 ± 0.003 | 0.050 ± 0.003 | 0.034 ± 0.007
Relative | 2.137 ± 0.143 | 1.876 ± 0.209 | 1.985 ± 0.152 | 2.104 ± 0.108 | 2.142 ± 0.056 | 1.530 ± 0.292
Female
n | 5 | 5 | 5 | 5 | 5 | 5
Necropsy body wt. | 19.8 ± 0.5 | 19.2 ± 1.1 | 20.0 ± 0.5 | 19.7 ± 0.7 | 18.7 ± 0.5 | 18.6 ± 0.8
Heart
Absolute | 0.108 ± 0.001^d^ | 0.105 ± 0.008 | 0.104 ± 0.003 | 0.102 ± 0.002 | 0.095 ± 0.005 | 0.088 ± 0.004^**^
Relative | 5.322 ± 0.072^d^ | 5.488 ± 0.232 | 5.201 ± 0.073 | 5.199 ± 0.135 | 5.060 ± 0.193 | 4.722 ± 0.077^*^
R. Kidney
Absolute | 0.139 ± 0.006 | 0.137 ± 0.003^d^ | 0.144 ± 0.005 | 0.140 ± 0.006 | 0.136 ± 0.002 | 0.142 ± 0.006
Relative | 6.992 ± 0.169 | 7.525 ± 0.507^d^ | 7.202 ± 0.082 | 7.122 ± 0.250 | 7.281 ± 0.175 | 7.649 ± 0.169
Liver
Absolute | 1.042 ± 0.061 | 0.992 ± 0.065 | 1.001 ± 0.040 | 1.065 ± 0.046 | 1.013 ± 0.067^b^ | —^e^
Relative | 52.400 ± 1.952 | 51.858 ± 3.063 | 49.963 ± 1.703 | 54.116 ± 2.084 | 54.057 ± 1.673^b^ | —^e^
Lung
Absolute | 0.178 ± 0.020 | 0.149 ± 0.006 | 0.155 ± 0.006 | 0.147 ± 0.004 | 0.142 ± 0.008 | 0.146 ± 0.003
Relative | 9.031 ± 1.096 | 7.819 ± 0.317 | 7.709 ± 0.143 | 7.502 ± 0.337 | 7.629 ± 0.503 | 7.878 ± 0.187
Thymus
Absolute | 0.061 ± 0.015 | 0.075 ± 0.006 | 0.068 ± 0.005 | 0.079 ± 0.005 | 0.065 ± 0.004 | 0.049 ± 0.003
Relative | 3.071 ± 0.716 | 3.958 ± 0.389 | 3.392 ± 0.239 | 4.006 ± 0.231 | 3.454 ± 0.190 | 2.638 ± 0.236

* Significantly different (P≤0.05) from the vehicle control group by William’s or Dunnett’s test

** P≤0.01

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

b n=3

c n=1

d n=4

e n=0

TABLE F5 Organ Weights and Organ-Weight-to-Body-Weight Ratios for C57BL/6 Mice in the 40-Week Gavage Study of Allyl Bromide^a^

| Vehicle Control | 8 mg/kg
Male
n | 14 | 15
Necropsy body wt. | 46.2 ± 1.8 | 46.4 ± 1.4
Heart
Absolute | 0.173 ± 0.006 | 0.164 ± 0.004
Relative | 3.765 ± 0.108 | 3.580 ± 0.144
R. Kidney
Absolute | 0.240 ± 0.006 | 0.238 ± 0.004
Relative | 5.261 ± 0.137 | 5.204 ± 0.211
Liver
Absolute | 2.050 ± 0.141 | 1.956 ± 0.083
Relative | 43.808 ± 1.601 | 42.082 ± 0.989
Lung
Absolute | 0.211 ± 0.005 | 0.210 ± 0.006
Relative | 4.686 ± 0.259 | 4.605 ± 0.217
R. Testis
Absolute | 0.094 ± 0.002 | 0.091 ± 0.002^b^
Relative | 2.068 ± 0.083 | 1.972 ± 0.079^b^
Thymus
Absolute | 0.054 ± 0.005 | 0.061 ± 0.008
Relative | 1.165 ± 0.097 | 1.321 ± 0.150
Female
n | 15 | 12
Necropsy body wt. | 39.4 ± 1.3 | 37.6 ± 1.6
Heart
Absolute | 0.148 ± 0.004^b^ | 0.148 ± 0.004
Relative | 3.812 ± 0.145^b^ | 3.995 ± 0.168
R. Kidney
Absolute | 0.190 ± 0.003 | 0.190 ± 0.005
Relative | 4.882 ± 0.172 | 5.112 ± 0.178
Liver
Absolute | 1.554 ± 0.042 | 1.489 ± 0.041
Relative | 39.741 ± 1.022 | 39.921 ± 0.850
Lung
Absolute | 0.224 ± 0.008 | 0.218 ± 0.007
Relative | 5.719 ± 0.190 | 5.937 ± 0.382
Thymus
Absolute | 0.055 ± 0.004^b^ | 0.053 ± 0.005
Relative | 1.429 ± 0.110^b^ | 1.443 ± 0.156

a Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). Differences from the vehicle control group are not significant by Dunnett’s test.

b n=14

TABLE F6 Organ Weights and Organ-Weight-to-Body-Weight Ratios for p53 Haploinsufficient Mice in the 40-Week Gavage Study of Allyl Bromide^a^

| Vehicle Control | 0.5 mg/kg | 1 mg/kg | 2 mg/kg | 4 mg/kg | 8 mg/kg
Male
n | 15 | 14 | 15 | 15 | 13 | 15
Necropsy body wt. | 47.7 ± 1.6 | 49.8 ± 1.6 | 49.9 ± 1.0 | 48.4 ± 1.8 | 50.3 ± 2.1 | 50.4 ± 1.1
Heart
Absolute | 0.169 ± 0.003^b^ | 0.183 ± 0.007 | 0.173 ± 0.003 | 0.173 ± 0.006 | 0.186 ± 0.005 | 0.182 ± 0.005
Relative | 3.589 ± 0.086^b^ | 3.678 ± 0.101 | 3.477 ± 0.082 | 3.600 ± 0.120 | 3.780 ± 0.200 | 3.626 ± 0.104
R. Kidney
Absolute | 0.256 ± 0.006 | 0.272 ± 0.010 | 0.269 ± 0.010 | 0.259 ± 0.011 | 0.276 ± 0.006 | 0.267 ± 0.005
Relative | 5.419 ± 0.188 | 5.492 ± 0.189 | 5.432 ± 0.231 | 5.432 ± 0.279 | 5.613 ± 0.292 | 5.315 ± 0.096
Liver
Absolute | 2.017 ± 0.103 | 2.228 ± 0.173^c^ | 1.954 ± 0.094 | 2.103 ± 0.162 | 2.273 ± 0.159 | 2.144 ± 0.127
Relative | 42.171 ± 1.424 | 44.148 ± 1.975^c^ | 39.022 ± 1.356 | 42.733 ± 1.909 | 44.562 ± 1.793 | 42.147 ± 1.699
Lung
Absolute | 0.223 ± 0.012 | 0.219 ± 0.007 | 0.222 ± 0.010 | 0.207 ± 0.007 | 0.234 ± 0.012 | 0.198 ± 0.004
Relative | 4.782 ± 0.344 | 4.480 ± 0.245 | 4.475 ± 0.220 | 4.367 ± 0.201 | 4.758 ± 0.322 | 3.956 ± 0.100
R. Testis
Absolute | 0.115 ± 0.002 | 0.119 ± 0.002 | 0.119 ± 0.002 | 0.115 ± 0.004 | 0.117 ± 0.003 | 0.119 ± 0.002^b^
Relative | 2.439 ± 0.070 | 2.413 ± 0.078 | 2.403 ± 0.055 | 2.396 ± 0.081 | 2.362 ± 0.093 | 2.385 ± 0.046^b^
Thymus
Absolute | 0.043 ± 0.003 | 0.052 ± 0.006 | 0.047 ± 0.005 | 0.048 ± 0.005 | 0.055 ± 0.007 | 0.054 ± 0.005
Relative | 0.913 ± 0.069 | 1.039 ± 0.103 | 0.948 ± 0.085 | 0.992 ± 0.103 | 1.114 ± 0.139 | 1.080 ± 0.104
Female
n | 13 | 14 | 13 | 14 | 15 | 13
Necropsy body wt. | 43.1 ± 2.2 | 43.5 ± 1.5 | 42.7 ± 1.6 | 40.1 ± 1.7 | 38.1 ± 1.7 | 44.8 ± 1.8
Heart
Absolute | 0.151 ± 0.004 | 0.151 ± 0.002 | 0.155 ± 0.004 | 0.149 ± 0.004 | 0.154 ± 0.004 | 0.155 ± 0.004
Relative | 3.571 ± 0.124 | 3.527 ± 0.121 | 3.680 ± 0.155 | 3.789 ± 0.151 | 4.114 ± 0.141^*^ | 3.490 ± 0.101
R. Kidney
Absolute | 0.202 ± 0.005 | 0.199 ± 0.003 | 0.194 ± 0.005 | 0.191 ± 0.006 | 0.207 ± 0.003 | 0.194 ± 0.006
Relative | 4.803 ± 0.194 | 4.627 ± 0.148 | 4.616 ± 0.182 | 4.830 ± 0.168 | 5.562 ± 0.235^*^ | 4.362 ± 0.119
Liver
Absolute | 1.695 ± 0.069 | 1.721 ± 0.074 | 1.554 ± 0.053 | 1.496 ± 0.052 | 1.593 ± 0.055 | 1.606 ± 0.043^d^
Relative | 39.730 ± 1.165 | 40.116 ± 2.226 | 36.739 ± 1.269 | 37.540 ± 0.749 | 42.265 ± 1.167 | 37.165 ± 1.174^d^
Lung
Absolute | 0.219 ± 0.009 | 0.209 ± 0.003^c^ | 0.221 ± 0.009 | 0.214 ± 0.008 | 0.232 ± 0.007 | 0.205 ± 0.004^d^
Relative | 5.282 ± 0.433 | 4.826 ± 0.150^c^ | 5.267 ± 0.290 | 5.449 ± 0.275 | 6.209 ± 0.273 | 4.609 ± 0.170^d^
Thymus
Absolute | 0.050 ± 0.004 | 0.047 ± 0.004 | 0.050 ± 0.005 | 0.054 ± 0.004 | 0.050 ± 0.004 | 0.051 ± 0.006
Relative | 1.182 ± 0.117 | 1.102 ± 0.105 | 1.190 ± 0.122 | 1.374 ± 0.095 | 1.326 ± 0.112 | 1.143 ± 0.140

* Significantly different (P≤0.05) from the vehicle control group by Dunnett’s test

a Organ weights (absolute weights) and body weights are given as grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

b n=14

c n=13

d n=12