# APPENDIX E GENETIC TOXICOLOGY

TABLE E1 Mutagenicity of Allyl Bromide in Salmonella typhimurium^a^

Strain | Dose (μg/Plate) | Revertants/Plate^b^
Strain | Dose (μg/Plate) | −S9 | | +30% hamster S9 | | +30% rat S9
Strain | Dose (μg/Plate) | Trial 1 | Trial 2 | Trial 1 | Trial 2 | Trial 1 | Trial 2
TA100 | 0 | 117 ± 3.8 | 123 ± 8.1 | 114 ± 5.5 | 119 ± 3.2 | 111 ± 3.9 | 135 ± 8.5
TA100 | 3 | | | 133 ± 8.4 | 126 ± 3.3 | 118 ± 0.9 | 139 ± 8.9
TA100 | 10 | 115 ± 0.9 | 126 ± 5.6 | 162 ± 3.9 | 143 ± 7.1 | 122 ± 1.8 | 150 ± 5.9
TA100 | 33 | 138 ± 4.1 | 136 ± 3.6 | 182 ± 11.3 | 165 ± 4.0 | 150 ± 7.6 | 166 ± 5.5
TA100 | 100 | 183 ± 3.1 | 171 ± 9.4 | 200 ± 10.0 | 186 ± 6.1 | 169 ± 3.8 | 187 ± 4.7
TA100 | 333 | 411 ± 23.4 | 388 ± 7.3 | 192 ± 3.4 | 214 ± 7.5 | 228 ± 15.0 | 227 ± 8.6
TA100 | 666 | | 352 ± 13.8
TA100 | 1,000 | 109 ± 5.2^c^
| | | | Weakly | Weakly | Weakly | Weakly
Trial summary | | Positive | Positive | Positive | Positive | Positive | Positive
Positive control^d^ | | 888 ± 23.3 | 872 ± 16.0 | 543 ± 11.6 | 508 ± 7.8 | 492 ± 8.0 | 470 ± 17.9
TA98 | 0 | 13 ± 2.3 | | 17 ± 1.0 | | 22 ± 1.7
TA98 | 3 | | | 19 ± 2.9 | | 15 ± 1.9
TA98 | 10 | 11 ± 0.6 | | 16 ± 1.3 | | 18 ± 1.8
TA98 | 33 | 12 ± 2.0 | | 18 ± 4.2 | | 21 ± 3.7
TA98 | 100 | 9 ± 0.9 | | 21 ± 2.6 | | 13 ± 1.9
TA98 | 333 | 10 ± 0.3 | | 18 ± 0.7 | | 19 ± 0.9
TA98 | 1,000 | 5 ± 0.3^c^
Trial summary | | Negative | | Negative | | Negative
Positive control | | 334 ± 22.1 | | 440 ± 15.4 | | 329 ± 14.0

a The study was performed at SRI International. The detailed protocol is presented by Zeiger et al. (1992). 0 μg/plate was the solvent control.

b Revertants are presented as mean ± standard error from three plates.

c Slight toxicity

d The positive controls in the absence of metabolic activation were sodium azide (TA100) and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with all strains was 2-aminoanthracene.

TABLE E2 Frequency of Micronuclei in Normochromatic Erythrocytes and Percent Polychromatic Erythrocytes in Peripheral Blood of FVB/N Mice Following Administration of Allyl Bromide by Gavage for 40 Weeks^a^

Compound | Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P-Value^c^ | PCEs^b^ (%)
Male
Corn Oil^d^ | 0 | 15 | 0.83 ± 0.20 | | 2.62 ± 0.20
Allyl Bromide | 8 | 14 | 1.25 ± 0.16 | 0.0594 | 2.86 ± 0.17
Female
Corn Oil^d^ | 0 | 15 | 0.90 ± 0.19 | | 2.95 ± 0.18
Allyl Bromide | 8 | 14 | 1.14 ± 0.19 | 0.1796 | 2.82 ± 0.12

a Study was performed at SITEK Research Laboratories. The detailed protocol is presented by MacGregor et al. (1990) and Witt et al. (2000). PCE=polychromatic erythrocyte; NCE=normochromatic erythrocyte.

b Mean ± standard error

c Pairwise comparison with the vehicle control group; significant at P≤0.05 (ILS, 1990)

d Vehicle control

TABLE E3 Frequency of Micronuclei in Normochromatic Erythrocytes and Percent Polychromatic Erythrocytes in Peripheral Blood of Tg.AC Hemizygous Mice Following Administration of Allyl Bromide by Gavage for 40 Weeks^a^

Compound | Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P-Value^c^ | PCEs^b^ (%)
Male
Corn Oil^d^ | 0 | 12 | 1.25 ± 0.32 | | 4.40 ± 0.34
Allyl Bromide | 0.5 | 9 | 0.89 ± 0.25 | 0.8659 | 3.92 ± 0.34
Allyl Bromide | 1 | 9 | 1.17 ± 0.25 | 0.5959 | 3.71 ± 0.19
Allyl Bromide | 2 | 12 | 0.92 ± 0.17 | 0.8665 | 3.94 ± 0.32
Allyl Bromide | 4 | 6 | 0.92 ± 0.27 | 0.8116 | 3.82 ± 0.29
Allyl Bromide | 8 | 11 | 1.27 ± 0.21 | 0.4726 | 3.41 ± 0.33
Allyl Bromide | | | P=0.303^e^
Female
Corn Oil^d^ | 0 | 9 | 0.44 ± 0.15 | | 4.32 ± 0.40
Allyl Bromide | 0.5 | 10 | 1.10 ± 0.18 | 0.0115 | 3.65 ± 0.17
Allyl Bromide | 1 | 8 | 0.69 ± 0.19 | 0.1719 | 4.29 ± 0.34
Allyl Bromide | 2 | 8 | 0.75 ± 0.30 | 0.1231 | 4.59 ± 0.67
Allyl Bromide | 4 | 11 | 0.91 ± 0.21 | 0.0402 | 4.19 ± 0.52
Allyl Bromide | 8 | 12 | 0.83 ± 0.17 | 0.0633 | 4.25 ± 0.25
Allyl Bromide | | | P=0.297^e^

a Study was performed at SITEK Research Laboratories. The detailed protocol is presented by MacGregor et al. (1990) and Witt et al. (2000). PCE=polychromatic erythrocyte; NCE=normochromatic erythrocyte.

b Mean ± standard error

c Pairwise comparison with the vehicle control group; significant at P≤0.005 (ILS, 1990)

d Vehicle control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test, significant at P≤0.025 (ILS, 1990)

TABLE E4 Frequency of Micronuclei in Normochromatic Erythrocytes and Percent Polychromatic Erythrocytes in Peripheral Blood of C57BL/6 Mice Following Administration of Allyl Bromide by Gavage for 40 Weeks^a^

Compound | Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P-Value^c^ | PCEs^b^ (%)
Male
Corn Oil^d^ | 0 | 14 | 1.61 ± 0.30 | | 3.56 ± 0.21
Allyl Bromide | 8 | 15 | 0.97 ± 0.18 | 0.9846 | 4.03 ± 0.26
Female
Corn Oil^d^ | 0 | 15 | 0.53 ± 0.18 | | 4.31 ± 0.29
Allyl Bromide | 8 | 12 | 0.96 ± 0.20 | 0.0339 | 3.86 ± 0.37

a Study was performed at SITEK Research Laboratories. The detailed protocol is presented by MacGregor et al. (1990) and Witt et al. (2000). PCE=polychromatic erythrocyte; NCE=normochromatic erythrocyte.

b Mean ± standard error

c Pairwise comparison with the vehicle control group; significant at P≤0.05 (ILS, 1990)

d Vehicle control

TABLE E5 Frequency of Micronuclei in Normochromatic Erythrocytes and Percent Polychromatic Erythrocytes in Peripheral Blood of p53 Haploinsufficient Mice Following Administration of Allyl Bromide by Gavage for 40 Weeks^a^

Compound | Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P-Value^c^ | PCEs^b^ (%)
Male
Corn Oil^d^ | 0 | 15 | 1.37 ± 0.24 | | 3.57 ± 0.18
Allyl Bromide | 0.5 | 14 | 1.64 ± 0.22 | 0.1952 | 4.61 ± 1.43
Allyl Bromide | 1 | 15 | 2.53 ± 0.22 | 0.0006 | 4.13 ± 0.74
Allyl Bromide | 2 | 15 | 1.50 ± 0.22 | 0.3330 | 3.79 ± 0.19
Allyl Bromide | 4 | 13 | 1.92 ± 0.31 | 0.0515 | 3.95 ± 0.18
Allyl Bromide | 8 | 15 | 1.63 ± 0.19 | 0.1994 | 3.49 ± 0.27
Allyl Bromide | | | P=0.577^e^
Female
Corn Oil^d^ | 0 | 13 | 0.58 ± 0.19 | | 3.99 ± 0.42
Allyl Bromide | 0.5 | 14 | 0.57 ± 0.12 | 0.5093 | 3.90 ± 0.46
Allyl Bromide | 1 | 13 | 0.81 ± 0.22 | 0.1904 | 3.15 ± 0.21
Allyl Bromide | 2 | 14 | 0.89 ± 0.23 | 0.1188 | 3.72 ± 0.27
Allyl Bromide | 4 | 15 | 1.00 ± 0.21 | 0.0613 | 4.15 ± 0.35
Allyl Bromide | 8 | 13 | 0.77 ± 0.17 | 0.2295 | 4.48 ± 0.69
Allyl Bromide | | | P=0.188^e^

a Study was performed at SITEK Research Laboratories. The detailed protocol is presented by MacGregor et al. (1990) and Witt et al. (2000). PCE=polychromatic erythrocyte; NCE=normochromatic erythrocyte.

b Mean ± standard error

c Pairwise comparison with the vehicle control group; significant at P≤0.005 (ILS, 1990)

d Vehicle control

e Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test, significant at P≤0.025 (ILS, 1990)