# APPENDIX D SUMMARY OF LESIONS IN P53 HAPLOINSUFFICIENT MICE IN THE 40-WEEK GAVAGE STUDY OF ALLYL BROMIDE

TABLE D1 Summary of the Incidence of Neoplasms in Male p53 Haploinsufficient Mice in the 40-Week Gavage Study of Allyl Bromide^a^

| Vehicle Control | 0.5 mg/kg | 1 mg/kg | 2 mg/kg | 4 mg/kg | 8 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | | | | | 1
Natural deaths | | 1 | | | 1
Survivors
Terminal sacrifice | 15 | 14 | 15 | 15 | 13 | 15
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Stomach, forestomach | (15) | (15) | (15) | (15) | (14) | (15)
Squamous cell papilloma | | | | 1 (7%)
Cardiovascular System
None
Endocrine System
None
General Body System
None
Genital System
None
Hematopoietic System
None
Integumentary System
None
Musculoskeletal System
Skeletal muscle | | | (1)
Rhabdomyosarcoma | | | 1 (100%)
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15) | (15)
Alveolar/bronchiolar adenoma | | | | 1 (7%) | 1 (7%)
Special Senses System
None
Urinary System
None
Neoplasm Summary
Total animals with primary neoplasms^b^ | | | 1 | 2 | 1
Total primary neoplasms | | | 1 | 2 | 1
Total animals with benign neoplasms | | | | 2 | 1
Total benign neoplasms | | | | 2 | 1
Total animals with malignant neoplasms | | | 1
Total malignant neoplasms | | | 1

a Number of animals examined microscopically at site and number of animals with neoplasm

b Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE D2 Summary of the Incidence of Nonneoplastic Lesions in Male p53 Haploinsufficient Mice in the 40-Week Gavage Study of Allyl Bromide^a^

| Vehicle Control | 0.5 mg/kg | 1 mg/kg | 2 mg/kg | 4 mg/kg | 8 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | | | | | 1
Natural deaths | | 1 | | | 1
Survivors
Terminal sacrifice | 15 | 14 | 15 | 15 | 13 | 15
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15) | (14) | (15)
Basophilic focus | | | | | 1 (7%)
Infiltration cellular, focal, lymphocyte | | | 1 (7%) | | | 2 (13%)
Tension lipidosis | | | | | | 1 (7%)
Hepatocyte, necrosis, focal | 1 (7%)
Hepatocyte, vacuolization cytoplasmic, diffuse | 5 (33%) | 7 (47%) | 11 (73%) | 7 (47%) | 8 (57%) | 6 (40%)
Hepatocyte, vacuolization cytoplasmic, focal | | | | 1 (7%) | | 1 (7%)
Hepatocyte, periportal, vacuolization cytoplasmic | 4 (27%) | 2 (13%) | 2 (13%) | 1 (7%) | 2 (14%) | 2 (13%)
Hepatocyte, centrilobular, vacuolization cytoplasmic | 3 (20%) | 1 (7%) | | 2 (13%) | 2 (14%) | 3 (20%)
Salivary glands | | | | | (1)
Infiltration cellular, focal, lymphocyte | | | | | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (15) | (14) | (15)
Epithelium, ulcer, focal | | | | 1 (7%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (15) | (14) | (15)
Atrophy | | 1 (7%) | 1 (7%)
Degeneration, diffuse | | | | 1 (7%) | | 1 (7%)
Hypertrophy, focal | 1 (7%)
Subcapsular, hyperplasia, focal | 1 (7%) | 1 (7%) | 1 (7%) | 1 (7%) | | 1 (7%)
Adrenal medulla | (15) | (15) | (15) | (15) | (14) | (15)
Degeneration, diffuse | | | | 1 (7%)
Thyroid gland | (15) | (15) | (14) | (15) | (14) | (15)
Follicular cell, hyperplasia, focal | | | 1 (7%)
General System
Tissue NOS | | | | (1)
Abdominal, fat, necrosis, focal | | | | 1 (100%)
Genital System
Epididymis | (15) | (15) | (15) | (15) | (14) | (15)
Granuloma sperm, focal | 1 (7%)
Necrosis, focal | | 1 (7%)
Testes | (15) | (15) | (15) | (15) | (14) | (15)
Degeneration, diffuse | | | | | | 1 (7%)
Inflammation, focal, granulomatous | 1 (7%)
Mineralization, focal | | 1 (7%)
Germinal epithelium, degeneration, diffuse | | | | | 1 (7%)
Germinal epithelium, degeneration, focal | | 1 (7%) | | | 2 (14%)
Hematopoietic System
Lymph node, mesenteric | (13) | (14) | (12) | (14) | (12) | (14)
Hyperplasia | | | | | 1 (8%)
Spleen | (15) | (15) | (15) | (15) | (14) | (15)
Hematopoietic cell proliferation | | 1 (7%) | 2 (13%) | 2 (13%) | 2 (14%) | 3 (20%)
Pigmentation | 1 (7%) | 1 (7%)
Integumentary System
Skin | (15) | (15) | (15) | (15) | (14) | (15)
Epidermis, control, hyperplasia, focal | | | | | | 1 (7%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15) | (15)
Alveolar epithelium, inflammation, chronic focal | | | | 1 (7%)
Perivascular, alveolus, inflammation, chronic active, focal | 1 (7%)
Special Senses System
None
Urinary System
Kidney | (15) | (15) | (15) | (15) | (14) | (15)
Cyst | | | 1 (7%)
Infiltration cellular, focal, lymphocyte | | | | 1 (7%)
Pelvis, infiltration cellular, focal, lymphocyte | 2 (13%) | | 2 (13%) | | 2 (14%) | 1 (7%)
Renal tubule, dilatation, diffuse | | | 1 (7%)

a Number of animals examined microscopically at site and number of animals with lesion

TABLE D3 Summary of the Incidence of Neoplasms in Female p53 Haploinsufficient Mice in the 40-Week Gavage Study of Allyl Bromide^a^

| Vehicle Control | 0.5 mg/kg | 1 mg/kg | 2 mg/kg | 4 mg/kg | 8 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | 1 | 2 | | | 1
Natural deaths | | | | 1 | | 1
Survivors
Terminal sacrifice | 13 | 14 | 13 | 14 | 15 | 13
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (14) | (15) | (15)
Lymphoma malignant | 1 (7%) | 1 (7%) | | | | 1 (7%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (14) | (15) | (15)
Lymphoma malignant | | | | | | 1 (7%)
Adrenal medulla | (15) | (15) | (15) | (14) | (15) | (15)
Lymphoma malignant | | | | | | 1 (7%)
General Body System
Tissue NOS | (1) | | | (1) | | (1)
Sarcoma | | | | 1 (100%)
Abdominal, sarcoma | | | | | | 1 (100%)
Pelvic, fibrosarcoma | 1 (100%)
Genital System
None
Hematopoietic System
Lymph node | | (1) | | | (1)
Lymphoma malignant | | 1 (100%)
Lymph node, mandibular | (15) | (14) | (15) | (14) | (15) | (13)
Lymphoma malignant | | 1 (7%)
Lymph node, mesenteric | (15) | (14) | (15) | (12) | (15) | (15)
Lymphoma malignant | | 1 (7%)
Lymph node, mediastinal | (15) | (14) | (15) | (14) | (15) | (14)
Lymphoma malignant | | 1 (7%) | | | | 1 (7%)
Spleen | (15) | (15) | (15) | (14) | (15) | (15)
Lymphoma malignant | 1 (7%) | 1 (7%) | | | | 1 (7%)
Thymus | (14) | (14) | (14) | (14) | (15) | (14)
Lymphoma malignant | 1 (7%) | | | | | 1 (7%)
Integumentary System
Skin | (15) | (15) | (15) | (14) | (15) | (15)
Subcutaneous tissue, osteosarcoma | 1 (7%)
Musculoskeletal System
Bone | (2) | (1) | (1)
Osteosarcoma | | | 1 (100%)
Mandible, osteosarcoma | | 1 (100%)
Vertebra, osteosarcoma | 1 (50%)
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15) | (15)
Lymphoma malignant | | | | | | 1 (7%)
Osteosarcoma, metastatic, skin | 1 (7%)
Special Senses System
None
Urinary System
None
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15) | (15) | (15)
Lymphoma malignant | 1 (7%) | 1 (7%) | | | | 1 (7%)
Neoplasm Summary
Total animals with primary neoplasms | 4 | 2 | 1 | 1 | | 2
Total primary neoplasms | 4 | 2 | 1 | 1 | | 2
Total animals with malignant neoplasms | 4 | 2 | 1 | 1 | | 2
Total malignant neoplasms | 4 | 2 | 1 | 1 | | 2
Total animals with metastatic neoplasms | 1
Total metastatic neoplasms | 1

a Number of animals examined microscopically at site and number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE D4 Summary of the Incidence of Nonneoplastic Lesions in Female p53 Haploinsufficient Mice in the 40-Week Gavage Study of Allyl Bromide^a^

| Vehicle Control | 0.5 mg/kg | 1 mg/kg | 2 mg/kg | 4 mg/kg | 8 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Moribund | 2 | 1 | 2 | | | 1
Natural deaths | | | | 1 | | 1
Survivors
Terminal sacrifice | 13 | 14 | 13 | 14 | 15 | 13
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Intestine small, duodenum | (15) | (15) | (15) | (14) | (15) | (14)
Polyp inflammatory, focal | | | | | | 1 (7%)
Liver | (15) | (15) | (15) | (14) | (15) | (15)
Infiltration cellular, focal, lymphocyte | 3 (20%) | 2 (13%) | 4 (27%) | 6 (43%) | 7 (47%) | 2 (13%)
Necrosis, focal | 1 (7%)
Tension lipidosis | | | | | | 1 (7%)
Hepatocyte, necrosis, focal | | | | 1 (7%) | 1 (7%) | 1 (7%)
Hepatocyte, vacuolization cytoplasmic, focal | | | | | 1 (7%) | 2 (13%)
Hepatocyte, periportal, vacuolization cytoplasmic | 8 (53%) | 8 (53%) | 8 (53%) | 6 (43%) | 3 (20%) | 5 (33%)
Salivary glands | | | | | | (1)
Infiltration cellular, focal, lymphocyte | | | | | | 1 (100%)
Stomach, forestomach | (15) | (15) | (15) | (14) | (15) | (14)
Hyperkeratosis, focal | | | | | 1 (7%)
Epithelium, hyperplasia, focal | | | | | 1 (7%)
Muscularis, inflammation, acute, focal | | | | | 1 (7%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (15) | (15) | (15) | (14) | (15) | (15)
Subcapsular, hyperplasia, focal | 13 (87%) | 14 (93%) | 15 (100%) | 12 (86%) | 12 (80%) | 13 (87%)
Parathyroid gland | | | (1)
Cyst | | | 1 (100%)
Pituitary gland | (14) | (14) | (15) | (13) | (15) | (13)
Cyst, focal | | | 1 (7%)
Thyroid gland | (14) | (15) | (15) | (14) | (14) | (15)
Ectopic thymus | 1 (7%) | | | | 1 (7%) | 1 (7%)
General Body System
None
Genital System
Ovary | (15) | (15) | (15) | (14) | (15) | (14)
Cyst | 1 (7%)
Degeneration | 1 (7%)
Uterus | (15) | (15) | (15) | (14) | (15) | (14)
Inflammation, acute | | | | | 1 (7%)
Thrombosis, focal | | | | | | 1 (7%)
Endometrium, hyperplasia, cystic | 13 (87%) | 13 (87%) | 14 (93%) | 13 (93%) | 14 (93%) | 14 (100%)
Hematopoietic System
Lymph node | | (1) | | | (1)
Hyperplasia | | | | | 1 (100%)
Lymph node, mandibular | (15) | (14) | (15) | (14) | (15) | (13)
Hyperplasia | | | 1 (7%) | 1 (7%) | 1 (7%)
Lymph node, mesenteric | (15) | (14) | (15) | (12) | (15) | (15)
Hyperplasia | | | | | 1 (7%)
Lymph node, mediastinal | (15) | (14) | (15) | (14) | (15) | (14)
Hyperplasia | | | 1 (7%)
Spleen | (15) | (15) | (15) | (14) | (15) | (15)
Hematopoietic cell proliferation | 8 (53%) | 6 (40%) | 7 (47%) | 10 (71%) | 9 (60%) | 7 (47%)
Hyperplasia, lymphoid | 1 (7%) | 1 (7%)
Pigmentation | 4 (27%) | 8 (53%) | 4 (27%) | 2 (14%) | 2 (13%) | 2 (13%)
Lymphoid follicle, depletion cellular, diffuse | | 1 (7%) | | | | 1 (7%)
Lymphoid follicle, hyperplasia | | 1 (7%)
Thymus | (14) | (14) | (14) | (14) | (15) | (14)
Atrophy, diffuse | 1 (7%) | | | | 2 (13%) | 1 (7%)
Atrophy, focal | | 1 (7%) | | | | 2 (14%)
Hyperplasia, focal | | | 1 (7%)
Integumentary System
Skin | (15) | (15) | (15) | (14) | (15) | (15)
Epidermis, hyperplasia, diffuse | 1 (7%)
Epidermis, hyperplasia, focal | | | 2 (13%) | | 1 (7%)
Subcutaneous tissue, edema, diffuse | 1 (7%)
Musculoskeletal System
Bone | (2) | (1) | (1)
Metatarsal, fracture | 1 (50%)
Nervous System
None
Respiratory System
Lung | (15) | (15) | (15) | (15) | (15) | (15)
Alveolar epithelium, hyperplasia, focal | | | | 1 (7%)
Alveolus, inflammation, chronic active, focal | | | | | 1 (7%)
Perivascular, infiltration cellular, lymphocyte | | | | | 1 (7%) | 2 (13%)
Special Senses System
None
Urinary System
Kidney | (15) | (15) | (15) | (14) | (15) | (15)
Pelvis, infiltration cellular, focal, lymphocyte | | 1 (7%) | | | | 2 (13%)
Renal tubule, dilatation, focal | 4 (27%) | | 3 (20%) | 1 (7%) | 2 (13%) | 2 (13%)

a Number of animals examined microscopically at site and number of animals with lesion