# APPENDIX C SUMMARY OF LESIONS IN C57BL/6 MICE IN THE 40-WEEK GAVAGE STUDY OF ALLYL BROMIDE

TABLE C1 Summary of the Incidence of Neoplasms and Nonneoplastic Lesions in Male C57BL/6 Mice in the 40-Week Gavage Study of Allyl Bromide^a^

| Vehicle Control | 8 mg/kg
Disposition Summary
Animals initially in study | 15 | 15
Early death
Moribund | 1
Survivors
Terminal sacrifice | 14 | 15
Animals examined microscopically | 15 | 15
Alimentary System
Liver | (15) | (15)
Infiltration cellular, focal, lymphocyte | 1 (7%)
Hepatocyte, vacuolization cytoplasmic, diffuse | 4 (27%) | 9 (60%)
Hepatocyte, periportal, vacuolization cytoplasmic | 2 (13%) | 1 (7%)
Hepatocyte, centrilobular, vacuolization cytoplasmic | 2 (13%)
Stomach, forestomach | (15) | (15)
Serosa, necrosis, focal | | 1 (7%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (15) | (15)
Atrophy | 4 (27%) | 3 (20%)
Hypertrophy, focal | 1 (7%)
Subcapsular, hyperplasia, focal | | 3 (20%)
Thyroid gland | (14) | (15)
Follicle, inflammation, acute, focal | 1 (7%)
General Body System
None
Genital System
Testes | (15) | (15)
Germinal epithelium, degeneration, diffuse | | 2 (13%)
Hematopoietic System
Spleen | (15) | (15)
Hematopoietic cell proliferation | 4 (27%) | 1 (7%)
Thymus | (15) | (15)
Atrophy, diffuse | 1 (7%)
Integumentary System
None
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15)
Perivascular, infiltration cellular, lymphocyte | 1 (7%)
Special Senses System
None
Urinary System
Kidney | (15) | (15)
Pelvis, infiltration cellular, focal, lymphocyte | 3 (20%) | 2 (13%)
Renal tubule, dilatation, diffuse | 1 (7%)

a Number of animals examined microscopically at site and number of animals with lesion

TABLE C2 Summary of the Incidence of Neoplasms and Nonneoplastic Lesions in Female C57BL/6 Mice in the 40-Week Gavage Study of Allyl Bromide^a^

| Vehicle Control | 8 mg/kg
Disposition Summary
Animals initially in study | 15 | 15
Early deaths
Moribund | | 2
Natural death | | 1
Survivors
Terminal sacrifice | 15 | 12
Animals examined microscopically | 15 | 15
Alimentary System
Intestine small, jejunum | (15) | (15)
Degeneration, focal | | 1 (7%)
Sarcoma | | 1 (7%)
Liver | (15) | (15)
Infiltration cellular, focal, lymphocyte | 2 (13%) | 6 (40%)
Hepatocyte, periportal, vacuolization, cytoplasmic | 9 (60%) | 6 (40%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (15) | (14)
Subcapsular, hyperplasia, focal | 14 (93%) | 10 (71%)
Thyroid gland | (15) | (15)
Ectopic thymus | | 1 (7%)
General Body System
Tissue NOS | | (1)
Sarcoma | | 1 (100%)
Genital System
Uterus | (15) | (15)
Endometrium, hyperplasia, cystic | 13 (87%) | 12 (80%)
Hematopoietic System
Lymph node | | (1)
Hyperplasia | | 1 (100%)
Inguinal, hyperplasia | | 1 (100%)
Lymph node, mandibular | (15) | (15)
Hyperplasia | 1 (7%) | 3 (20%)
Lymph node, mediastinal | (15) | (11)
Hyperplasia | | 1 (9%)
Spleen | (15) | (14)
Hematopoietic cell proliferation | 9 (60%) | 12 (86%)
Pigmentation | 7 (47%) | 4 (29%)
Thymus | (15) | (14)
Atrophy, diffuse | | 2 (14%)
Atrophy, focal | | 1 (7%)
Integumentary System
Skin | (15) | (15)
Epidermis, ulcer, chronic active, diffuse | | 1 (7%)
Epidermis, control, inflammation, chronic active, diffuse | | 1 (7%)
Epidermis, control, ulcer, chronic active, diffuse | | 1 (7%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15)
Alveolus, inflammation, chronic active, focal | | 1 (7%)
Perivascular, infiltration cellular, lymphocyte | | 2 (13%)
Special Senses System
None
Urinary System
Kidney | (15) | (15)
Mineralization, focal | 1 (7%)
Pelvis, infiltration cellular, focal, lymphocyte | | 2 (13%)
Renal tubule, dilatation, focal | 2 (13%) | 4 (27%)
Neoplasm Summary
Total animals with primary neoplasms^b^ | | 1
Total primary neoplasms | | 2
Total animals with malignant neoplasms | | 1
Total malignant neoplasms | | 2

a Number of animals examined microscopically at site and number of animals with lesion

b Primary neoplasms: all neoplasms except metastatic neoplasms