# APPENDIX B SUMMARY OF LESIONS IN TG.AC HEMIZYGOUS MICE IN THE 40-WEEK GAVAGE STUDY OF ALLYL BROMIDE

TABLE B1 Summary of the Incidence of Neoplasms in Male Tg.AC Hemizygous Mice in the 40-Week Gavage Study of Allyl Bromide^a^

| Vehicle Control | 0.5 mg/kg | 1 mg/kg | 2 mg/kg | 4 mg/kg | 8 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Accidental deaths | | 1 | | 1 | 1 | 1
Moribund | 2 | 2 | 3 | 2 | 4 | 1
Natural deaths | 1 | 3 | 3 | | 4 | 2
Survivors
Terminal sacrifice | 12 | 9 | 9 | 12 | 6 | 11
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (14) | (15) | (14) | (15) | (14) | (15)
Leukemia erythrocytic | | | 1 (7%) | | 1 (7%) | 1 (7%)
Salivary glands | | (1) | (1) | (1)
Duct, carcinoma | | 1 (100%) | 1 (100%) | 1 (100%)
Stomach, forestomach | (15) | (14) | (14) | (15) | (13) | (14)
Squamous cell papilloma | 5 (33%) | 3 (21%) | 5 (36%) | 5 (33%) | 5 (38%) | 5 (36%)
Squamous cell papilloma, multiple | 1 (7%) | 2 (14%) | 1 (7%) | 1 (7%)
Tooth | (5) | (5) | (4) | (3) | (6) | (4)
Odontogenic tumor | 5 (100%) | 5 (100%) | 3 (75%) | 3 (100%) | 6 (100%) | 3 (75%)
Cardiovascular System
None
Endocrine System
None
General Body System
None
Genital System
None
Hematopoietic System
Spleen | (15) | (14) | (14) | (15) | (14) | (15)
Leukemia erythrocytic | | | 1 (7%) | | 1 (7%) | 1 (7%)
Integumentary System
Skin | (15) | (15) | (15) | (15) | (14) | (15)
Keratoacanthoma | | | 3 (20%)
Squamous cell papilloma | 4 (27%) | 1 (7%) | 5 (33%) | 2 (13%) | 1 (7%) | 1 (7%)
Squamous cell papilloma, multiple | 1 (7%) | | 2 (13%) | 1 (7%) | 1 (7%) | 3 (20%)
Conjunctiva, squamous cell carcinoma | | | | | 1 (7%)
Lip, squamous cell papilloma | | 1 (7%) | 1 (7%) | | | 1 (7%)
Lip, squamous cell papilloma, multiple | 1 (7%) | | | 1 (7%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15) | (14) | (15) | (14) | (15)
Alveolar/bronchiolar adenoma | 1 (7%) | | | 1 (7%) | 2 (14%)
Alveolar/bronchiolar carcinoma | | 1 (7%)
Carcinoma, metastatic, salivary glands | | | 1 (7%)
Leukemia erythrocytic | | | 1 (7%)
Special Senses System
None
Urinary System
None
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15) | (15) | (15)
Leukemia erythrocytic | | | 1 (7%) | | 1 (7%) | 1 (7%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 11 | 10 | 11 | 11 | 12 | 10
Total primary neoplasms | 18 | 14 | 22 | 15 | 17 | 14
Total animals with benign neoplasms | 9 | 5 | 9 | 9 | 8 | 7
Total benign neoplasms | 13 | 7 | 17 | 11 | 9 | 10
Total animals with malignant neoplasms | | 2 | 2 | 1 | 2 | 1
Total malignant neoplasms | | 2 | 2 | 1 | 2 | 1
Total animals with metastatic neoplasms | | | 1
Total metastatic neoplasms | | | 1
Total animals with uncertain neoplasms-benign or malignant | 5 | 5 | 3 | 3 | 6 | 3
Total uncertain neoplasms | 5 | 5 | 3 | 3 | 6 | 3

a Number of animals examined microscopically at the site and the number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE B2 Summary of the Incidence of Nonneoplastic Lesions in Male Tg.AC Hemizygous Mice in the 40-Week Gavage Study of Allyl Bromide^a^

| Vehicle Control | 0.5 mg/kg | 1 mg/kg | 2 mg/kg | 4 mg/kg | 8 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Accidental deaths | | 1 | | 1 | 1 | 1
Moribund | 2 | 2 | 3 | 2 | 4 | 1
Natural deaths | 1 | 3 | 3 | | 4 | 2
Survivors
Terminal sacrifice | 12 | 9 | 9 | 12 | 6 | 11
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Esophagus | | (1) | | (1) | (1) | (1)
Muscularis, periesophageal tissue, inflammation, chronic active, diffuse | | | | 1 (100%)
Periesophageal tissue, inflammation, chronic active, diffuse | | | | | 1 (100%) | 1 (100%)
Periesophageal tissue, inflammation, chronic active, focal | | 1 (100%)
Liver | (14) | (15) | (14) | (15) | (14) | (15)
Necrosis, focal | | 1 (7%) | | | | 1 (7%)
Hepatocyte, necrosis, focal | 2 (14%) | 3 (20%) | 5 (36%) | | 2 (14%)
Hepatocyte, vacuolization cytoplasmic, diffuse | | 1 (7%)
Hepatocyte, vacuolization cytoplasmic, focal | | | | 1 (7%) | 1 (7%) | 2 (13%)
Hepatocyte, centrilobular, hypertrophy | 1 (7%)
Hepatocyte, centrilobular, vacuolization cytoplasmic | 2 (14%) | | 2 (14%) | | | 1 (7%)
Serosa, inflammation, chronic active, focal | | 1 (7%)
Sinusoid, inflammation, focal | | | 1 (7%)
Mesentery | (1) | (1) | | (2)
Fat, necrosis, focal | 1 (100%) | 1 (100%) | | 2 (100%)
Pancreas | | | | | | (1)
Acinus, atrophy, diffuse | | | | | | 1 (100%)
Salivary glands | | (1) | (1) | (1)
Necrosis, focal | | | 1 (100%)
Tooth | (5) | (5) | (4) | (3) | (6) | (4)
Peridontal tissue, inflammation, chronic active, focal | | | | | | 1 (25%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (15) | (14) | (14) | (14) | (12) | (14)
Atrophy | 15 (100%) | 13 (93%) | 14 (100%) | 14 (100%) | 10 (83%) | 12 (86%)
Degeneration, focal | | | 1 (7%)
Hypertrophy, focal | 13 (87%) | 10 (71%) | 9 (64%) | 11 (79%) | 10 (83%) | 11 (79%)
Subcapsular, hyperplasia, focal | | | | 1 (7%)
Zona reticularis, vacuolization cytoplasmic, focal | 1 (7%) | | | 1 (7%) | 1 (8%) | 1 (7%)
Thyroid gland | (15) | (13) | (14) | (15) | (9) | (14)
Inflammation, chronic active, focal | | 1 (8%)
General Body System
Tissue NOS | | | (1) | | | (1)
Fat, necrosis, focal | | | | | | 1 (100%)
Mediastinum, inflammation, chronic active focal | | | 1 (100%)
Genital System
Preputial gland | (1) | (2) | (2) | (1) | (4) | (2)
Ectasia | 1 (100%) | 1 (50%) | 2 (100%) | 1 (100%) | 4 (100%) | 2 (100%)
Inflammation, chronic active, focal | | 1 (50%)
Seminal vesicle | | | | (1) | | (1)
Dilatation | | | | 1 (100%)
Bilateral, dilatation | | | | | | 1 (100%)
Testes | (15) | (15) | (15) | (15) | (14) | (14)
Germinal epithelium, degeneration, diffuse | | | | 1 (7%)
Germinal epithelium, degeneration, focal | 1 (7%) | | 5 (33%) | 1 (7%)
Hematopoietic System
Lymph node, mandibular | (15) | (13) | (14) | (15) | (13) | (15)
Hyperplasia | 1 (7%) | 1 (8%) | 2 (14%) | | 3 (23%) | 1 (7%)
Hyperplasia, histiocytic | | 1 (8%)
Lymph node, mesenteric | (14) | (14) | (14) | (15) | (12) | (14)
Hyperplasia | | 1 (7%)
Inflammation, chronic active, focal | | | 1 (7%)
Lymph node, mediastinal | (14) | (13) | (14) | (15) | (10) | (14)
Hyperplasia | | 1 (8%) | 1 (7%)
Spleen | (15) | (14) | (14) | (15) | (14) | (15)
Congestion | | 1 (7%) | | | 1 (7%)
Hematopoietic cell proliferation | 14 (93%) | 14 (100%) | 13 (93%) | 15 (100%) | 12 (86%) | 13 (87%)
Inflammation, chronic active, focal | | | 1 (7%)
Pigmentation | 8 (53%) | 10 (71%) | 9 (64%) | 12 (80%) | 6 (43%) | 11 (73%)
Lymphoid follicle, depletion cellular | 1 (7%) | 1 (7%) | | 1 (7%) | 1 (7%)
Thymus | (15) | (13) | (12) | (15) | (10) | (13)
Atrophy, diffuse | 3 (20%) | 3 (23%) | 2 (17%) | 2 (13%) | 3 (30%) | 1 (8%)
Atrophy, focal | 1 (7%) | 2 (15%) | 1 (8%) | 4 (27%) | 1 (10%) | 1 (8%)
Hyperplasia | | | 2 (17%)
Hyperplasia, focal | | | | | 1 (10%)
Integumentary System
Skin | (15) | (15) | (15) | (15) | (14) | (15)
Hyperkeratosis, focal | | | | | | 1 (7%)
Dermis, inflammation, chronic active, focal | | | | | | 1 (7%)
Epidermis, hyperplasia, focal | 1 (7%) | | | | | 2 (13%)
Subcutaneous tissue, inflammation, chronic active, focal | | 1 (7%) | | 1 (7%)
Subcutaneous tissue, necrosis, focal | | | 1 (7%) | | | 1 (7%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15) | (14) | (15) | (14) | (15)
Inflammation, chronic active, focal | | | 1 (7%)
Alveolar epithelium, hyperplasia, focal | | 1 (7%)
Alveolus, hemorrhage, focal | | | 1 (7%) | 1 (7%) | | 1 (7%)
Arteriole, artery, inflammation, chronic active, focal | | | | | 2 (14%)
Arteriole, capillary, perivascular, inflammation, acute | | 1 (7%)
Mediastinum, inflammation, chronic active, diffuse | | | | | | 1 (7%)
Perivascular, infiltration cellular, focal, lymphocyte | | 1 (7%) | 1 (7%)
Perivascular, infiltration cellular, lymphocyte | 1 (7%) | | | | 1 (7%) | 1 (7%)
Serosa, mediastinum, inflammation, chronic active, diffuse | | | 1 (7%)
Special Senses System
Eye | (1) | | | | (1)
Retina, atrophy | 1 (100%) | | | | 1 (100%)
Urinary System
Kidney | (15) | (14) | (14) | (15) | (14) | (14)
Inflammation, acute, focal | | 1 (7%)
Inflammation, chronic active, focal | | | 1 (7%)
Bilateral, cortex, inflammation, acute, focal | | | | | 1 (7%)
Capsule, cortex, inflammation, chronic active, focal | | 1 (7%)
Cortex, inflammation, acute, focal | | | | | 2 (14%)
Renal tubule, degeneration, focal | | | | | 2 (14%)
Renal tubule, dilatation, diffuse | | | 1 (7%) | | 1 (7%)
Renal tubule, dilatation, focal | 1 (7%) | 1 (7%) | 1 (7%) | 1 (7%)

a Number of animals examined microscopically at site and number of animals with lesion

TABLE B3 Summary of the Incidence of Neoplasms in Female Tg.AC Hemizygous Mice in the 40-Week Gavage Study of Allyl Bromide^a^

| Vehicle Control | 0.5 mg/kg | 1 mg/kg | 2 mg/kg | 4 mg/kg | 8 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Accidental deaths | 2
Moribund | 2 | 3 | 4 | 6 | 1 | 3
Natural deaths | 2 | 2 | 3 | 1 | 3
Survivors
Terminal sacrifice | 9 | 10 | 8 | 8 | 11 | 12
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Liver | (15) | (15) | (15) | (15) | (14) | (15)
Leukemia erythrocytic | | 1 (7%)
Lymphoma malignant | 2 (13%) | 1 (7%) | | 1 (7%)
Salivary glands | | | (3)
Duct, carcinoma | | | 3 (100%)
Stomach, forestomach | (14) | (15) | (12) | (13) | (14) | (15)
Squamous cell papilloma | 5 (36%) | 8 (53%) | 4 (33%) | 7 (54%) | 5 (36%) | 6 (40%)
Squamous cell papilloma, multiple | 3 (21%) | 2 (13%) | 2 (17%) | | 2 (14%) | 4 (27%)
Tooth | (2) | (3) | (6) | (7) | (3) | (3)
Odontogenic tumor | 2 (100%) | 3 (100%) | 6 (100%) | 6 (86%) | 2 (67%) | 3 (100%)
Cardiovascular System
Heart | | (1) | | (1)
Lymphoma malignant | | 1 (100%)
Endocrine System
Adrenal cortex | (13) | (14) | (12) | (13) | (12) | (15)
Lymphoma malignant | | 1 (7%)
Adrenal medulla | (13) | (14) | (12) | (12) | (12) | (15)
Lymphoma malignant | | 1 (7%)
Pituitary gland | (11) | (14) | (14) | (13) | (14) | (14)
Lymphoma malignant | | | | 1 (8%)
General Body System
None
Genital System
Ovary | (13) | (15) | (14) | (14) | (13) | (15)
Lymphoma malignant | 1 (8%) | 1 (7%)
Uterus | (13) | (15) | (13) | (14) | (12) | (15)
Lymphoma malignant | | 1 (7%)
Hematopoietic System
Lymph node, mesenteric | (13) | (14) | (12) | (15) | (12) | (15)
Lymphoma malignant | | 1 (7%)
Lymph node, mediastinal | (14) | (15) | (14) | (14) | (12) | (14)
Lymphoma malignant | | 1 (7%)
Spleen | (15) | (14) | (15) | (15) | (13) | (15)
Leukemia erythrocytic | | 1 (7%)
Lymphoma malignant | 2 (13%) | 1 (7%) | | 1 (7%)
Integumentary System
Skin | (15) | (15) | (15) | (15) | (14) | (15)
Squamous cell papilloma | 1 (7%) | 1 (7%) | 3 (20%) | 3 (20%) | 5 (36%) | 1 (7%)
Squamous cell papilloma, multiple | | | | | 1 (7%)
Dermis, fibrosarcoma | | | | | | 1 (7%)
Lip, squamous cell papilloma | 1 (7%) | 1 (7%) | | | 1 (7%) | 3 (20%)
Vulva, squamous cell papilloma | 2 (13%) | 4 (27%) | 1 (7%) | 5 (33%) | 4 (29%) | 6 (40%)
Vulva, squamous cell papilloma, multiple | | | | 1 (7%) | 1 (7%) | 1 (7%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (14) | (15) | (15) | (15) | (14) | (15)
Alveolar/bronchiolar adenoma | | | | 2 (13%)
Alveolar/bronchiolar carcinoma | | | | | | 1 (7%)
Lymphoma malignant | | 1 (7%) | | 1 (7%)
Special Senses System
Harderian gland | | | | | | (1)
Adenoma | | | | | | 1 (100%)
Urinary System
Kidney | (15) | (14) | (14) | (15) | (13) | (15)
Lymphoma malignant | 1 (7%) | 1 (7%) | | 1 (7%)
Systemic Lesions
Multiple organs^b^ | (15) | (15) | (15) | (15) | (15) | (15)
Leukemia erythrocytic | | 1 (7%)
Lymphoma malignant | 2 (13%) | 1 (7%) | | 1 (7%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 10 | 13 | 10 | 14 | 11 | 14
Total primary neoplasms | 16 | 21 | 19 | 25 | 21 | 27
Total animals with benign neoplasms | 9 | 10 | 8 | 9 | 11 | 14
Total benign neoplasms | 12 | 16 | 10 | 18 | 19 | 22
Total animals with malignant neoplasms | 2 | 2 | 3 | 1 | | 2
Total malignant neoplasms | 2 | 2 | 3 | 1 | | 2
Total animals with uncertain neoplasms-benign or malignant | 2 | 3 | 6 | 6 | 2 | 3
Total uncertain neoplasms | 2 | 3 | 6 | 6 | 2 | 3

a Number of animals examined microscopically at site and number of animals with neoplasm

b Number of animals with any tissue examined microscopically

c Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE B4 Summary of the Incidence of Nonneoplastic Lesions in Female Tg.AC Hemizygous Mice in the 40-Week Gavage Study of Allyl Bromide^a^

| Vehicle Control | 0.5 mg/kg | 1 mg/kg | 2 mg/kg | 4 mg/kg | 8 mg/kg
Disposition Summary
Animals initially in study | 15 | 15 | 15 | 15 | 15 | 15
Early deaths
Accidental deaths | 2
Moribund | 2 | 3 | 4 | 6 | 1 | 3
Natural deaths | 2 | 2 | 3 | 1 | 3
Survivors
Terminal sacrifice | 9 | 10 | 8 | 8 | 11 | 12
Animals examined microscopically | 15 | 15 | 15 | 15 | 15 | 15
Alimentary System
Esophagus | (2)
Muscularis, epithelium, necrosis, diffuse | 1 (50%)
Muscularis, periesophageal tissue, inflammation, chronic active, focal | 1 (50%)
Periesophageal tissue, foreign body, focal | 1 (50%)
Intestine small, duodenum | (13) | (14) | (11) | (12) | (13) | (15)
Serosa, inflammation, acute, focal | | | | | 1 (8%)
Liver | (15) | (15) | (15) | (15) | (14) | (15)
Hematopoietic cell proliferation | 1 (7%) | | 1 (7%) | 1 (7%)
Infiltration cellular, diffuse, polymorphonuclear | | | | | 1 (7%) | 1 (7%)
Inflammation, acute, focal | | | 1 (7%) | | 1 (7%)
Inflammation, chronic active, diffuse | | | 1 (7%)
Necrosis, chronic active, focal | | | | | 1 (7%)
Necrosis, focal | 2 (13%) | 2 (13%) | 3 (20%) | 2 (13%) | 1 (7%) | 2 (13%)
Centrilobular, vacuolization cytoplasmic | | | | | | 1 (7%)
Hepatocyte, degeneration, focal | | | 1 (7%)
Hepatocyte, necrosis, focal | 1 (7%) | 1 (7%) | 3 (20%) | 5 (33%) | 3 (21%) | 4 (27%)
Hepatocyte, vacuolization cytoplasmic, diffuse | 4 (27%) | 5 (33%) | 3 (20%) | | 4 (29%) | 3 (20%)
Hepatocyte, vacuolization cytoplasmic, focal | 2 (13%) | 2 (13%) | 1 (7%) | 4 (27%) | 2 (14%) | 3 (20%)
Hepatocyte, periportal, vacuolization cytoplasmic | | | 1 (7%) | | | 2 (13%)
Hepatocyte, centrilobular, vacuolization cytoplasmic | | | | | | 1 (7%)
Serosa, inflammation, acute, focal | | | | | 1 (7%)
Pancreas | (1) | (1) | (1) | | (3)
Inflammation, acute, diffuse | | | | | 1 (33%)
Necrosis, focal | | 1 (100%)
Acinus, atrophy, diffuse | | | 1 (100%)
Stomach, forestomach | (14) | (15) | (12) | (13) | (14) | (15)
Muscularis, serosa, inflammation, acute, focal | | | | | 1 (7%)
Stomach, glandular | (13) | (14) | (11) | (13) | (13) | (15)
Serosa, inflammation, acute, focal | | | | | 1 (8%)
Cardiovascular System
Blood vessel | (1)
Aorta, inflammation, chronic active, focal | 1 (100%)
Heart | | (1) | | (1)
Atrium, thrombosis, focal | | | | 1 (100%)
Endocrine System
Adrenal cortex | (13) | (14) | (12) | (13) | (12) | (15)
Atrophy | 4 (31%) | 6 (43%) | 9 (75%) | 3 (23%) | 11 (92%) | 4 (27%)
Mineralization, focal | | | | | | 1 (7%)
Subcapsular, hyperplasia, focal | 2 (15%) | 4 (29%) | 3 (25%) | 9 (69%) | 5 (42%) | 6 (40%)
Zona reticularis, hyperplasia, diffuse | | | | | 1 (8%)
Zona reticularis, infiltration cellular, focal, lymphocyte | | | | | 1 (8%)
Zona reticularis, diffuse | 6 (46%) | 8 (57%) | 6 (50%) | 10 (77%) | 9 (75%) | 12 (80%)
Zona reticularis, vacuolization cytoplasmic, focal | 6 (46%) | 4 (29%) | 5 (42%) | 2 (15%) | 1 (8%) | 3 (20%)
Thyroid gland | (13) | (13) | (12) | (14) | (12) | (14)
Ectopic thymus | | | 1 (8%) | | 1 (8%)
Follicle, cyst, focal | 1 (8%) | | | | 1 (8%)
General Body System
None
Genital System
Ovary | (13) | (15) | (14) | (14) | (13) | (15)
Angiectasis, focal | | 1 (7%)
Atrophy | | 2 (13%) | 2 (14%) | | 1 (8%)
Cyst | | | 1 (7%) | | 1 (8%)
Cyst, focal | | | | | | 1 (7%)
Degeneration | 1 (8%) | | 2 (14%) | 1 (7%) | 1 (8%) | 1 (7%)
Inflammation, acute, diffuse | | | | | 1 (8%)
Inflammation, chronic active, diffuse | | | | | 1 (8%)
Inflammation, diffuse | | | | | | 1 (7%)
Bilateral, inflammation, chronic active, diffuse | 1 (8%)
Bilateral, periovarian tissue, cyst | | | | | 1 (8%)
Corpus luteum, inflammation, chronic active, focal | | | 1 (7%)
Periovarian tissue, inflammation, acute, focal | | | | | | 1 (7%)
Periovarian tissue, inflammation, chronic active, diffuse | 1 (8%)
Periovarian tissue, inflammation, chronic active, focal | | 1 (7%) | | 1 (7%)
Periovarian tissue, rete ovarii, inflammation, acute, focal | | | 1 (7%) | | 1 (8%)
Uterus | (13) | (15) | (13) | (14) | (12) | (15)
Atrophy | | | | | 1 (8%)
Hydrometra | | 1 (7%) | | 2 (14%)
Inflammation, acute, diffuse | | 1 (7%)
Inflammation, acute, focal | | | 1 (8%)
Inflammation, chronic active, diffuse | | | 1 (8%)
Endometrium, hyperplasia, cystic | 11 (85%) | 10 (67%) | 8 (62%) | 4 (29%) | 10 (83%) | 13 (87%)
Endometrium, inflammation, acute, focal | 1 (8%)
Serosa, inflammation, acute, focal | | | | | 1 (8%)
Vagina | | | (1)
Inflammation, chronic active, diffuse | | | 1 (100%)
Hematopoietic System
Lymph node | | | | | (1)
Iliac, hyperplasia | | | | | 1 (100%)
Renal, hyperplasia | | | | | 1 (100%)
Lymph node, mandibular | (14) | (15) | (12) | (14) | (12) | (15)
Hyperplasia | 2 (14%) | 1 (7%) | | | 2 (17%) | 2 (13%)
Inflammation, acute, focal | | | 1 (8%)
Necrosis, focal | | | | | | 1 (7%)
Lymph node, mesenteric | (13) | (14) | (12) | (15) | (12) | (15)
Hyperplasia | 1 (8%)
Lymph node, mediastinal | (14) | (15) | (14) | (14) | (12) | (14)
Atrophy | | 1 (7%)
Hyperplasia | | | 1 (7%) | | 1 (8%)
Inflammation, diffuse | | | | | | 1 (7%)
Spleen | (15) | (14) | (15) | (15) | (13) | (15)
Hematopoietic cell proliferation | 13 (87%) | 11 (79%) | 15 (100%) | 13 (87%) | 12 (92%) | 14 (93%)
Pigmentation | 10 (67%) | 11 (79%) | 10 (67%) | 14 (93%) | 11 (85%) | 14 (93%)
Capsule, inflammation, acute, focal | | | | | 2 (15%)
Lymphoid follicle, depletion cellular | 1 (7%) | 1 (7%) | | 1 (7%)
Thymus | (13) | (13) | (12) | (13) | (11) | (15)
Atrophy, diffuse | 5 (38%) | 3 (23%) | | 2 (15%) | | 1 (7%)
Atrophy, focal | | 2 (15%) | 1 (8%) | 3 (23%) | 2 (18%) | 6 (40%)
Integumentary System
Mammary gland | (1)
Dilatation, focal | 1 (100%)
Skin | (15) | (15) | (15) | (15) | (14) | (15)
Dermis, fibrosis, focal | | | 1 (7%)
Dermis, subcutaneous tissue, inflammation, chronic active, diffuse | | | 1 (7%)
Epidermis, hyperplasia, focal | | | 1 (7%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (14) | (15) | (15) | (15) | (14) | (15)
Alveolus, hemorrhage, focal | | | | 1 (7%) | | 1 (7%)
Alveolus, hyperplasia, focal, histiocytic | | | 1 (7%)
Alveolus, inflammation, chronic, focal | | | | | 1 (7%)
Arteriole, necrosis, focal | | | 1 (7%)
Mediastinum, inflammation, acute, focal | 1 (7%) | | | | 1 (7%)
Perivascular, infiltration cellular, lymphocyte | | | 1 (7%) | | 1 (7%) | 1 (7%)
Serosa, mediastinum, inflammation, chronic active, focal | | 1 (7%)
Special Senses System
None
Urinary System
Kidney | (15) | (14) | (14) | (15) | (13) | (15)
Infiltration cellular, focal, lymphocyte | | | | | | 1 (7%)
Inflammation, chronic active, focal | | | 1 (7%) | | 1 (8%)
Necrosis, focal | | | 1 (7%)
Bilateral, inflammation, acute, focal | 1 (7%) | | | | | 1 (7%)
Bilateral, nephropathy, diffuse | 1 (7%)
Capsule, inflammation, acute, focal | | | 1 (7%)
Cortex, inflammation, acute, focal | | 1 (7%)
Cortex, pelvis, inflammation, chronic active, focal | 1 (7%)
Papilla, inflammation, acute, focal | | | | 1 (7%)
Renal tubule, degeneration, focal | | 1 (7%)
Renal tubule, dilatation, diffuse | 1 (7%) | 1 (7%) | 1 (7%)
Renal tubule, dilatation, focal | | | | 2 (13%) | 1 (8%)

a Number of animals examined microscopically at site and number of animals with lesion