# APPENDIX A SUMMARY OF LESIONS IN FVB/N MICE IN THE 40-WEEK GAVAGE STUDY OF ALLYL BROMIDE

TABLE A1 Summary of the Incidence of Neoplasms and Nonneoplastic Lesions in Male FVB/N Mice in the 40-Week Gavage Study of Allyl Bromide^a^

| Vehicle Control | 8 mg/kg
Disposition Summary
Animals initially in study | 15 | 15
Early death
Accidental death | | 1
Survivors
Terminal sacrifice | 15 | 14
Animals examined microscopically | 15 | 15
Alimentary System
Esophagus | | (1)
Epithelium, hyperplasia, diffuse | | 1 (100%)
Muscularis, periesophageal tissue, inflammation, chronic active, focal | | 1 (100%)
Liver | (15) | (15)
Tension lipidosis | | 1 (7%)
Hepatocyte, necrosis, focal | 1 (7%) | 1 (7%)
Hepatocyte, vacuolization cytoplasmic, focal | 1 (7%)
Hepatocyte, centrilobular, vacuolization cytoplasmic | 3 (20%) | 2 (13%)
Hepatocyte, centrilobular, vacuolization cytoplasmic, focal | 1 (7%)
Serosa, mineralization, focal | 1 (7%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (15) | (14)
Atrophy | 15 (100%) | 14 (100%)
Hypertrophy, focal | 13 (87%) | 14 (100%)
Subcapsular, hyperplasia, focal | 1 (7%)
Thyroid gland | (15) | (15)
Ectopic thymus | 1 (7%)
General Body System
None
Genital System
Preputial gland | (2) | (2)
Ectasia | 2 (100%) | 2 (100%)
Infiltration cellular, focal, lymphocyte | | 1 (50%)
Testes | (15) | (15)
Germinal epithelium, degeneration, focal | 2 (13%) | 2 (13%)
Hematopoietic System
Lymph node, mediastinal | (14) | (15)
Hyperplasia | 1 (7%)
Spleen | (15) | (15)
Hematopoietic cell proliferation | 15 (100%) | 13 (87%)
Pigmentation | 11 (73%) | 11 (73%)
Lymphoid follicle, atrophy | | 1 (7%)
Thymus | (15) | (15)
Atrophy, diffuse | | 1 (7%)
Atrophy, focal | 2 (13%) | 3 (20%)
Hyperplasia, focal | | 1 (7%)
Integumentary System
Skin | (15) | (15)
Subcutaneous tissue, inflammation, chronic active, focal | 1 (7%) | 1 (7%)
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15)
Alveolar/bronchiolar adenoma | | 2 (13%)
Alveolar/bronchiolar adenoma, multiple | | 1 (7%)
Hemorrhage, focal | | 1 (7%)
Alveolar epithelium, hyperplasia, focal | 1 (7%) | 1 (7%)
Mediastinum, inflammation, acute, focal | | 1 (7%)
Perivascular, infiltration cellular, focal lymphocyte | | 1 (7%)
Special Senses System
None
Urinary System
Kidney | (15) | (15)
Renal tubule, degeneration, focal | | 1 (7%)
Renal tubule, dilatation, diffuse | 1 (7%)
Renal tubule, dilatation, focal | 1 (7%)
Neoplasm Summary
Total animals with primary neoplasms^b^ | | 3
Total primary neoplasms | | 3
Total animals with benign neoplasms | | 3
Total benign neoplasms | | 3

a Number of animals examined microscopically at site and number of animals with lesion

b Primary neoplasms: all neoplasms except metastatic neoplasms

TABLE A2 Summary of the Incidence of Neoplasms and Nonneoplastic Lesions in Female FVB/N Mice in the 40-Week Gavage Study of Allyl Bromide^a^

| Vehicle Control | 8 mg/kg
Disposition Summary
Animals initially in study | 15 | 15
Early death
Moribund | | 1
Survivors
Terminal sacrifice | 15 | 14
Animals examined microscopically | 15 | 15
Alimentary System
Liver | (15) | (15)
Hepatocyte, necrosis, focal | 2 (13%) | 2 (13%)
Hepatocyte, vacuolization cytoplasmic, diffuse | 2 (13%) | 2 (13%)
Hepatocyte, vacuolization cytoplasmic, focal | 2 (13%) | 3 (20%)
Hepatocyte, centrilobular, vacuolization cytoplasmic | | 1 (7%)
Kupffer cell, hyperplasia, diffuse | | 1 (7%)
Cardiovascular System
None
Endocrine System
Adrenal cortex | (15) | (15)
Atrophy | 2 (13%) | 2 (13%)
Subcapsular, hyperplasia, focal | 8 (53%) | 9 (60%)
Zona reticularis, vacuolization cytoplasmic, diffuse | 12 (80%) | 13 (87%)
Zona reticularis, vacuolization cytoplasmic, focal | 2 (13%) | 2 (13%)
General Body System
None
Genital System
Ovary | (15) | (15)
Hemorrhage, focal | | 2 (13%)
Inflammation, acute, focal | | 1 (7%)
Inflammation, chronic active, focal | | 1 (7%)
Uterus | (15) | (15)
Hydrometra | 2 (13%) | 1 (7%)
Endometrium, hyperplasia, cystic | 14 (93%) | 15 (100%)
Hematopoietic System
Spleen | (15) | (15)
Hematopoietic cell proliferation | 15 (100%) | 15 (100%)
Pigmentation | 15 (100%) | 14 (93%)
Lymphoid follicle, hyperplasia | 1 (7%)
Thymus | (15) | (14)
Atrophy, focal | 4 (27%) | 3 (21%)
Integumentary System
None
Musculoskeletal System
None
Nervous System
None
Respiratory System
Lung | (15) | (15)
Alveolar/bronchiolar adenoma | 2 (13%) | 1 (7%)
Alveolar epithelium, hyperplasia, focal | 1 (7%)
Alveolus, hemorrhage, focal | 1 (7%)
Special Senses System
None
Urinary System
Kidney | (15) | (15)
Renal tubule, dilatation, focal | 2 (13%) | 2 (13%)
Neoplasm Summary
Total animals with primary neoplasms^b^ | 2 | 1
Total primary neoplasms | 2 | 1
Total animals with benign neoplasms | 2 | 1
Total benign neoplasms | 2 | 1

a Number of animals examined microscopically at site and number of animals with lesion

b Primary neoplasms: all neoplasms except metastatic neoplasms