# REFERENCES

The Aldrich Library of FT-IR Spectra (1985). 1st ed. (C.J. Pouchert, Ed.), Vol. 1. Aldrich Chemical Company, Inc., Milwaukee, WI.
American Industrial Hygiene Association (1981). Workplace Environmental Exposure Level Guide. Am. Ind. Hyg. Assoc. J. 42, A-53–A-55.6784565
Awogi, T., Murata, K., Uejima, M., Kuwahara, T., Asanami, S., Shimono, K., and Morita, T. (1992). Induction of micronucleated reticulocytes by potassium bromate and potassium chromate in CD-1 male mice. Mutat. Res. 278, 181–185.1372703
Ballmaier, D., and Epe, B. (1995). Oxidative DNA damage induced by potassium bromate under cell-free conditions and in mammalian cells. Carcinogenesis 16, 335–342.7859366
Boorman, G.A., Montgomery, C.A., Jr., Eustis, S.L., Wolfe, M.J., McConnell, E.E., and Hardisty, J.F. (1985). Quality assurance in pathology for rodent carcinogenicity studies. In Handbook of Carcinogen Testing (H.A. Milman and E.K. Weisburger, Eds.), pp. 345–357. Noyes Publications, Park Ridge, NJ.
Boorman, G.A., Hickman, R.L., Davis, G.W., Rhodes, L.S., White, N.W., Griffin, T.A., Mayo, J., and Hamm, T.E., Jr. (1986). Serological titers to murine viruses in 90-day and 2-year studies. In Complications of Viral and Mycoplasmal Infections in Rodents to Toxicology Research and Testing (T.E. Hamm, Jr., Ed.), pp. 11–23. Hemisphere Publishing Corporation, Washington, DC.
Bucher, J.R. (1998). Update on National Toxicology Program (NTP) assays with genetically altered or “transgenic” mice. Environ. Health Perspect. 106, 619–621.9755135
Bull, R.J., Birnbaum, L.S., Cantor, K.P., Rose, J.B., Butterworth, B.E., Pegram, R., and Tuomisto, J. (1995). Water chlorination: Essential process or cancer hazard? Fundam. Appl. Toxicol. 28, 155–166.8835225
Bull, R.J., and Kopfler, F.C. (1991). Health Effects of Disinfectants and Disinfection By-Products. American Water Works Association Research Foundation, Denver.
Cannon, R.E., Spalding, J.W., Trempus, C.S., Szczesniak, C.J., Virgil, K.M., Humble, M.C., and Tennant, R.W. (1997). Kinetics of wound-induced v-Ha-ras transgene expression and papilloma development in transgenic Tg.AC mice. Mol. Carcinog. 20, 108–114.9328441
Code of Federal Regulations (CFR) 16, §1700.14.
Code of Federal Regulations (CFR) 21, Part 58.
Code of Federal Regulations (CFR) 40, §141.64.
Cosmetic Ingredient Review Expert Panel (CIREP) (1994). Final report on the safety assessment of sodium bromate and potassium bromate. J. Am. Coll. Toxicol. 13, 400–414.
Cox, D.R. (1972). Regression models and life-tables. J. R. Stat. Soc. B34, 187–220.
DeAngelo, A.B., George, M.H., Kilburn, S.R., Moore, T.M., and Wolf, D.C. (1998). Carcinogenicity of potassium bromate administered in the drinking water to male B6C3F_1_ mice and F344/N rats. Toxicol. Pathol. 26, 587–594.9789944
Dixon, W.J., and Massey, F.J., Jr. (1951). Introduction to Statistical Analysis, 2nd ed., pp. 276–278, 412. McGraw-Hill Book Company, Inc., New York.
Donehower, L.A., Harvey, M., Slagel, B.L., McArthur, M.J., Montgomery, C.A., Butel, J.S., and Bradley, A. (1992). Mice deficient for p53 are developmentally normal but susceptible to spontaneous tumours. Nature 356, 215–221.1552940
Dunn, O.J. (1964). Multiple comparisons using rank sums. Technometrics 6, 241–252.
Dunnett, C.W. (1955). A multiple comparison procedure for comparing several treatments with a control. J. Am. Stat. Assoc. 50, 1096–1121.
Eckhardt, K., Gocke, E., King, M-T., and Wild, D. (1982). Mutagenic activity of chlorate, bromate, and iodate. Mutat. Res. 97, 185 (Abstr.).
Federal Register (1992). Modification in voluntary filing of cosmetic product ingredient and cosmetic raw material composition statements. Final Rule. Vol. 57, pp. 3128–3130.
Fisher, N., Hutchinson, J.B., Berry, R., Hardy, J., Ginocchio, A.V., and Waite, V. (1979). Long-term toxicity and carcinogenicity studies of the bread improver potassium bromate. 1. Studies in rats. Food Cosmet. Toxicol. 17, 33–39.437610
Fujie, K., Shimazu, H., Matsuda, M., and Sugiyama, T. (1988). Acute cytogenetic effects of potassium bromate on rat bone marrow cells in vivo. Mutat. Res. 206, 455–458.3205264
Fujii, M., Oikawa, K., Saito, H., Fukuhara, C., Onosaka, S., and Tanaka, K. (1984). Metabolism of potassium bromate in rats. I. In vivo studies. Chemosphere 13, 1207–1212.
Gart, J.J., Chu, K.C., and Tarone, R.E. (1979). Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. JNCI 62, 957–974.285297
Ginocchio, A.V., Waite, V., Hardy, J., Fisher, N., Hutchinson, J.B., and Berry, R. (1979). Long-term toxicity and carcinogenicity studies of the bread improver potassium bromate. 2. Studies in mice. Food Cosmet. Toxicol. 17, 41–47.437611
Giri, U., Iqbal, M., and Athar, M. (1999). Potassium bromate (KBrO_3_) induces renal proliferative response and damage by elaborating oxidative stress. Cancer Lett. 135, 181–188.10096427
Glaze, W.H. (1986). Reaction products of ozone: A review. Environ. Health Perspect. 69, 151–157.3545802
Gradus, D., Rhoads, M., Bergstrom, L.B., and Jordan, S.C. (1984). Acute bromate poisoning associated with renal failure and deafness presenting as hemolytic uremic syndrome. Am. J. Nephrol. 4, 188–191.6742011
Guo, T.L., Munson, J.A., and White, K.L. (2001). Final range-finding report: Immunotoxicity of sodium bromate in female B6C3F_1_ mice. Report to the National Toxicology Program. Virginia Commonwealth University, Richmond, VA.
Haag, W.R., and Holgné, J. (1983). Ozonation of bromide-containing waters: Kinetics of formation of hypobromus acid and bromate. Environ. Sci. Technol. 17, 261–267.
Hardisty, J.F., and Boorman, G.A. (1990). Thyroid gland. In Pathology of the Fischer Rat (G.A. Boorman, S.L. Eustis, M.R. Elwell, C.A. Montgomery, and W.F. MacKenzie Eds.), pp. 519–534. Academic Press, San Diego.
Harris, C.C. (1996a). Structure and function of the p53 tumor suppressor gene: Clues for rational cancer therapeutic strategies. J. Natl. Cancer Inst. 88, 1442–1455.8841019
Harris, C.C. (1996b). p53 Tumor suppressor gene: From the basic research laboratory to the clinic - an abridged historical perspective. Carcinogenesis 17, 1187–1198.8681432
Harris, C.C. (1996c). The 1995 Walter Hubert Lecture - molecular epidemiology of human cancer: Insights from the mutational analysis of the p53 tumour-suppressor gene. Brit. J. Cancer 73, 261–269.8562328
Hayashi, J., Kishi, M., Sofuni, T., and Ishidate, M. Jr. (1988). Micronucleus tests in mice on 39 food additives and eight miscellaneous chemicals. Food Chem. Toxicol. 26, 487–500.3169648
Hayashi, M., Sutou, S., Shimada, H., Sato, S., Sasaki, Y.F., and Wakata, A. (1989). Difference between intraperitoneal and oral gavage application in the micronucleus test. The 3rd collaborative study by CSGMT/JEMS.HMS. Collaborative Study Group for the Micronucleus Test/Mammalian Mutagenesis Study Group of the Environmental Mutagen Society of Japan. Mutat. Res. 223, 329–344.
Hazardous Substances Data Bank (HSDB) (2003). National Institute for Occupational Safety and Health, HSDB database available through the National Library of Medicine MEDLARS System.
Hirai, O., Miyamae, Y., Fujino, Y., Izumi, H., Miyamoto, A., and Noguchi, H. (1991). Prior bleeding enhances the sensitivity of the in vivo micronucleus test. Mutat. Res. 264, 109–114.1944391
Hollander, M., and Wolfe, D.A. (1973). Nonparametric Statistical Methods, pp. 120–123. John Wiley and Sons, New York.
Honchel, R., Rosenzweig, B.A., Thompson, K.L., Blanchard, K.T., Furst, S.M., Stoll, R.E., and Sistare, F.D. (2001). Loss of palindromic symmetry in Tg.AC mice with a nonresponder phenotype. Mol. Carcinog. 30, 99–110.11241757
Hooth, M.J., DeAngelo, A.B., George, M.H., Gaillard, E.T., Travlos, G.S., Boorman, G.A., and Wolf, D.C. (2001). Subchronic sodium chlorate exposure in drinking water results in a concentration-dependent increase in rat thyroid follicular cell hyperplasia. Toxicol. Pathol. 29, 250–259.11421493
Integrated Laboratory Systems (ILS) (1990). Micronucleus Data Management and Statistical Analysis Software, Version 1.4. ILS, P.O. Box 13501, Research Triangle Park, NC 27707.
Ishidate, M., Sofuni, T., Yoshikawa, K., Hayashi, M., Nohmi, T., Sawada, M., and Matsuoka, A. (1984). Primary mutagenicity screening of food additives currently used in Japan. Food Chem. Toxicol. 22, 623–636.6381265
Jonckheere, A.R. (1954). A distribution-free k-sample test against ordered alternatives. Biometrika 41, 133–145.
Kaplan, E.L., and Meier, P. (1958). Nonparametric estimation from incomplete observations. J. Am. Stat. Assoc. 53, 457–481.
Kitto, W., and Dumars, K.W. (1949). Potassium bromate poisoning. J. Pediatr. 35, 197–200.18135538
Kurata, Y., Diwan, B.A., and Ward, J.M. (1992). Lack of renal tumour-initiating activity of a single dose of potassium bromate, a genotoxic renal carcinogen in male F344/NCr rats. Food Chem. Toxicol. 30, 251–259.1618449
Kurokawa, Y., Hayashi, Y., Maekawa, A., Takahashi, M., and Kukubo, T. (1982). Induction of renal cell tumors in F-344 rats by oral administration of potassium bromate, a food additive. Gann 73, 335–338.7117760
Kurokawa, Y., Hayashi, Y., Maekawa, A., Takahashi, M., Kokubo, T., and Odashima, S. (1983a). Carcinogenicity of potassium bromate administered orally to F344 rats. J. Natl. Cancer Inst. 71, 965–971.6580498
Kurokawa, Y., Takahashi, M., Kokubo, T., Ohno, Y., and Hayashi, Y. (1983b). Enhancement by potassium bromate of renal tumorigenesis initiated by N-ethyl-N-hydroxyethylnitrosamine in F-344 rats. Gann 74, 607–610.6642133
Kurokawa, Y., Takamura, N., Matsushima, Y., Imazawa, T., and Hayashi, Y. (1984). Studies on the promoting and complete carcinogenic activities of some oxidizing chemicals in skin carcinogenesis. Cancer Lett. 24, 299–304.6437666
Kurokawa, Y., Aoki, S., Imazawa, T., Hayashi, Y., Matsushima, Y., and Takamura, N. (1985). Dose-related enhancing effect of potassium bromate on renal tumorigenesis in rats initiated with N-ethyl-N-hydroxyethylnitrosamine. Jpn. J. Cancer Res. 76, 583–589.3928554
Kurokawa, Y., Aoki, S., Matsushima, Y., Takamura, N., Imazawa, T., and Hayashi, Y. (1986a). Dose-response studies on the carcinogenicity of potassium bromate in F344 rats after long-term oral administration. J. Natl. Cancer Inst. 77, 977–982.3463824
Kurokawa, Y., Takayama, S., Konishi, Y., Hiasa, Y., Asahina, S., Takahashi, M., Maekawa, A., and Hayashi, Y. (1986b). Long-term in vivo carcinogenicity tests of potassium bromate, sodium hypochlorite, and sodium chlorite conducted in Japan. Environ. Health Perspect. 69, 221–235.3816726
Kurokawa, Y., Matsushima, Y., Takamura, N., Imazawa, T., and Hayashi, Y. (1987a). Relationship between the duration of treatment and the incidence of renal cell tumors in male F344 rats administered potassium bromate. Jpn. J. Cancer Res. 78, 358–364.3108216
Kurokawa, Y., Takamura, N., Matsuoka, C., Imazawa, T., Matsushima, Y., Onodera, H., and Hayashi, Y. (1987b). Comparative studies on lipid peroxidation in the kidney of rats, mice, and hamsters and on the effect of cysteine, glutathione, and diethyl maleate treatment on mortality and nephrotoxicity after administration of potassium bromate. J. Am. Coll. Toxicol. 6, 489.
Kurokawa, Y., Maekawa, A., Takahashi, M., and Hayashi, Y. (1990). Toxicity and carcinogenicity of potassium bromate – a new renal carcinogen. Environ. Health Perspect. 87, 309–335.2269236
Kutom, A., Bazilinski, N.G., Magana, L., and Dunea, G. (1990). Bromate intoxication: Hairdresser’s anuria. Am. J. Kidney Dis. XV, 84–85.
Leder, A., Kuo, A., Cardiff, R.D., Sinn, E., and Leder, P. (1990). v-Ha-ras transgene abrogates the initiation step in mouse skin tumorigenesis: Effects of phorbol esters and retinoic acid. Proc. Natl. Acad. Sci. 87, 9178–9182.2251261
Lichtenberg, R., Zeller, W.P., Gatson, R., and Hurley, R.M. (1989). Clinical and laboratory observations: Bromate poisoning. J. Pediatr. 114, 891–894.2715904
McConnell, E.E., Solleveld, H.A., Swenberg, J.A., and Boorman, G.A. (1986). Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. JNCI 76, 283–289.3456066
MacGregor, J.T., Wehr, C.M., Henika, P.R., and Shelby, M.D. (1990). The in vivo erythrocyte micronucleus test: Measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam. Appl. Toxicol. 14, 513–522.2111256
McGuire, M.J., Krasner, S.W., and Gramith, J.T. (1990). Comments on bromide levels in state project water and impacts on control of disinfection byproducts. September. Metropolitan Water District of Southern California, Los Angeles, CA.
Mahler, J.F., and Elwell, M.R. (1999). Pituitary gland. In Pathology of the Mouse (R.R. Maronpot, G.A. Boorman, and B.W. Gaul, Eds.), pp. 504–505. Cache River Press, Vienna, IL.
Mahler, J.F., Stokes, W., Mann, P.C., Takaoka, M., and Maronpot, R.R. (1996). Spontaneous lesions in aging FVB/N mice. Toxicol. Pathol. 24, 710–716.8994298
Mahler, J.F., Flagler, N.D., Malarkey, D.E., Mann, P.C., Haseman, J.K., and Eastin, W. (1998). Spontaneous and chemically induced proliferative lesions in Tg.AC transgenic and p53-heterozygous mice. Toxicol. Pathol. 26, 501–511.9715509
Maronpot, R.R., and Boorman, G.A. (1982). Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol. Pathol. 10, 71–80.28094716
Matsumoto, I., Morizono, T., and Paparella, M.M. (1980). Hearing loss following potassium bromate: Two case reports. Otolaryngol. Head Neck Surg. 88, 625–629.7443270
Matsushima, Y., Takamura, N., Imazawa, T., Kurokawa, Y., and Hayashi, Y. (1986). Lack of carcinogenicity of potassium bromate after subcutaneous injection to newborn mice and newborn rats. Sci. Rep. Res. Inst. Tohoku Univ. 33, 22–26.
The Merck Index (1983). 10th ed. (M. Windholz, Ed.). Merck and Company, Rahway, NJ.
Morita, T., Asano, N., Awogi, T., Sasaki, Y.F., Sato, S.-I., Shimada, H., Sutou, S., Suzuki, T., Wakata, A., Sofuni, T., and Hayashi, M. (1997). Evaluation of the rodent micronucleus assay in the screening of IARC carcinogens (Groups 1, 2A and 2B): The summary report of the 6th collaborative study by CSGMT/JEMS MMS. Mutat. Res. 389, 3–122.9062586
Nakajima, M., Kitazawa, M., Oba, K., Kitagawa, Y., and Toyoda, Y. (1989). Effect of route of administration in the micronucleus test with potassium bromate. Mutat. Res. 223, 399–402.2747726
Nakano, K., Okada, S., Toyokuni, S., and Midorikawa, O. (1989). Renal changes induced by chronic oral administration of potassium bromate or ferric nitrilotriacetate in Wistar rats (In Japanese, English abstract). Jpn. Arch. Intern. Med. 36, 41–47.
National Toxicology Program (NTP) (1987). Toxicology and Carcinogenesis Studies of Bromodichloromethane (CAS No. 75-27-4) in F344/N Rats and B6C3F_1_ Mice (Gavage Studies). Technical Report Series No. 321. NIH Publication No. 88-2537. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (1996). Sodium Bromate: Short Term Reproductive and Developmental Toxicity Study When Administered to Sprague-Dawley Rats in the Drinking Water. R.O.W. Sciences, Rockville, MD.
National Toxicology Program (NTP) (1998). Toxicology and Carcinogenesis Studies of Chloroprene (CAS No. 126-99-8) in F344/N Rats and B6C3F_1_ Mice (Inhalation Studies). Technical Report Series No. 467. NIH Publication No. 98-3957. U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, Research Triangle Park, NC.
National Toxicology Program (NTP) (2001). Sodium Bromate: Reproductive Assessment by Continuous Breeding when Administered to Sprague-Dawley Rats in Drinking Water. Unaudited Draft Final Report. Study Number 7244-209. TherImmune Research Corporation, 15 Firstfield Road, Gaithersburg, MD.
National Toxicology Program (NTP) (2005a). Toxicology and Carcinogenesis Studies of Sodium Chlorate (CAS No. 7775-09-9) in F344/N Rats and B6C3F_1_ Mice (Drinking Water Studies). Technical Report Series No. 517. NIH Publication No. 06-4457. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2005b). Toxicology Studies of Aspartame (CAS No. 22839-47-0) in Genetically Modified (FVB Tg.AC Hemizygous) and B6.129-Cdkn2a^tm1Rdp^ (N2) Deficient Mice and Carcinogenicity Studies of Aspartame in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Feed Studies). Report Series No. GMM 1. NIH Publication No. 06-4459. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
National Toxicology Program (NTP) (2006a). Toxicology Studies of Bromodichloromethane (CAS No. 75-27-4) in Genetically Modified (FVB Tg.AC Hemizygous) Mice (Dermal, Drinking Water, and Gavage Studies) and Carcinogenicity Studies of Bromodichloromethane in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Drinking Water and Gavage Studies). Report Series No. GMM 5. NIH Publication No. 07-4422. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC. (in press)
National Toxicology Program (NTP) (2006b). Toxicology Study of Diisopropylcarbodiimide (CAS No. 693-13-0) in Genetically Modified (FVB Tg.AC Hemizygous) Mice and Carcinogenicity Study of Diisopropylcarbodiimide in Genetically Modified [B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient] Mice (Dermal Studies). Report Series No. GMM 10. NIH Publication No. 07-4427. National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services, Research Triangle Park, NC.
Parker, W.A., and Barr, J.R. (1951). Potassium bromate poisoning. Brit. Med. J. 1, 1363.14839269
Pavelka, S., Babický, A., Vobecký, M., Lener, J., and Švandová, E. (2000a). Bromide kinetics and distribution in the rat. I. Biokinetics of ^82^Br-bromide. Biol. Trace Elem. Res. 76, 57–66.10999430
Pavelka, S., Babický, A., Vobecký, M., and Lener, J. (2000b). Bromide kinetics and distribution in the rat. II. Distribution of bromide in the body. Biol. Trace Elem. Res. 76, 67–74.10999431
Pavelka, S. (2004). Metabolism of bromide and its interference with the metabolism of iodine. Physiol. Res. 53, S81–S90.15119938
Pritchard, J.B., French, J.E., Davis, B.J., and Haseman, J.K. (2003). The role of transgenic mouse models in carcinogen identification. Environ. Health Perspect. 111, 444–454.12676597
Quick, C.A., Chole, R.A., and Mauer, S.M. (1975). Deafness and renal failure due to potassium bromate poisoning. Arch. Otolaryngol. 101, 494–495.1156239
Rao, G.N., Haseman, J.K., and Edmondson, J. (1989a). Influence of viral infections on body weight, survival, and tumor prevalence in Fischer 344/NCr rats on two-year studies. Lab. Anim. Sci. 39, 389–393.2554057
Rao, G.N., Piegorsch, W.W., Crawford, D.D., Edmondson, J., and Haseman, J.K. (1989b). Influence of viral infections on body weight, survival, and tumor prevalence of B6C3F1 (C57BL/6N × C3H/HeN) mice in carcinogenicity studies. Fundam. Appl. Toxicol. 13, 156–164.2767355
Rook, J.J. (1974). Formation of haloforms during chlorination of natural waters. Water Treat. Exam. 23, 234–236.
Sai, K., Takagi, A., Umemura, T., Hasegawa, R., and Kurokawa, Y. (1991). Relation of 8-hydroxydeoxyguanosine formation in rat kidney to lipid peroxidation, glutathione level and relative organ weight after a single administration of potassium bromate. Jpn. J. Cancer Res. 82, 165–169.1900820
Sai, K., Hayashi, M., Takagi, A., Hasegawa, R., Sofuni, T., and Kurokawa Y. (1992a). Effects of antioxidants on induction of micronuclei in rat peripheral blood reticulocytes by potassium bromate. Mutat. Res. 269, 113–118.1381463
Sai, K., Uchiyama, S., Ohno, Y., Hasegawa, R., and Kurokawa, Y. (1992b). Generation of active oxygen species in vitro by the interaction of potassium bromate with rat kidney cell. Carcinogenesis 12, 333–339.
Shirley, E. (1977). A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics 33, 386–389.884197
Spalding, J.W., Momma, J., Elwell, M.R., and Tennant, R.W. (1993). Chemically induced skin carcinogenesis in a transgenic mouse line (TG.AC) carrying a v-HA-ras gene. Carcinogenesis 14, 1335–1341.8330346
Spalding, J.W., French, J.E., Tice, R.R., Furedi-Machacek, M., Haseman, J.K., and Tennant, R.W. (1999). Development of a transgenic mouse model for carcinogenesis bioassays: Evaluation of chemically induced skin tumors in Tg.AC mice. Toxicol. Sci. 49, 241–254.10416269
Spalding, J.W., French, J.E., Stasiewicz, S., Furedi-Machacek, M., Conner, F., Tice, R.R., and Tennant, R.W. (2000). Responses of transgenic mouse lines p53^(+/−)^ and Tg.AC to agents tested in conventional carcinogenicity bioassays. Toxicol. Sci. 53, 213–223.10696769
Speit, G., Haupter, S., Schutz, P., and Kreis, P. (1999). Comparative evaluation of the genotoxic properties of potassium bromate and potassium superoxide in V79 Chinese hamster cells. Mutat. Res. 439, 213–221.10023063
Suzuki, Y., Nagae, Y., Ishikawa, T., Watanabe, Y., Nagashima, T., Matsukubo, K., and Shimizu, H. (1989). Effect of erythropoietin on the micronucleus test. Environ. Mol. Mutagen. 13, 314–318.2737182
Takamura, N., Kurokawa, Y., Matsushima, Y, Imazawa, T., Onodera, H., and Hayashi, Y. (1985). Long-term oral administration of potassium bromate in male Syrian golden hamsters. Sci. Rep. Res. Inst. Tohoku Univ. 32, 43–46.
Tanaka, K., Oikawa, K., Fukuhara, C., Saito, H., Onosaka, S., Min, K.-S., and Fujii, M. (1984). Metabolism of potassium bromate in rats. II. In vitro studies. Chemosphere 13, 1213–1219.
Tarone, R.E. (1975). Tests for trend in life table analysis. Biometrika 62, 679–682.
Tennant, R.W., French, J.E., and Spalding, J.W. (1995). Identifying chemical carcinogens and assessing potential risk in short-term bioassays using transgenic mouse models. Environ. Health Perspect. 103, 942–950.8529591
Tennant, R.W., Spalding, J., and French, J.E. (1996). Evaluation of transgenic mouse bioassays for identifying carcinogens and noncarcinogens. Mutat. Res. 365, 119–127.8898993
Tennant, R.W., Stasiewicz, S., Mennear, J., French, J.E., and Spalding, J.W. (1999). Genetically altered mouse models for identifying carcinogens. IARC Sci. Publ. 146, 123–150.
Tennant, R.W., Stasiewicz, S., Eastin, W.C., Mennear, J.H., and Spalding, J.W. (2001). The Tg.AC (v-Ha-ras) transgenic mouse: Nature of the model. Toxicol. Pathol. 29, 51–59.11695562
Trempus, C.S., Mahler, J.F., Ananthaswamy, H.N., Loughlin, S.M., French, J.E., and Tennant, R.W. (1998). Photocarcinogenesis and susceptibility to UV radiation in the v-Ha-ras transgenic Tg.AC mouse. J. Invest. Dermatol. 111, 445–451.9740239
Umemura, T., Sai, K., Tagaki, A., Hasegawa, R., and Kurokawa, Y. (1993). A possible role for cell proliferation in potassium bromate (KBrO_3_) carcinogenesis. J. Cancer Res. Clin. Oncol. 119, 463–469.7685357
Umemura T., Takagi, A., Sai, K., Hasegawa, R., and Kurokawa, Y. (1998). Oxidative DNA damage and cell proliferation in kidneys of male and female rats during 13-weeks exposure to potassium bromate (KBrO_3_). Arch. Toxicol. 72, 264–269.9630011
Virginia Commonwealth University (VCU) (2000). Final Range-Finding Report: Immunotoxicity of Sodium Bromate in Female B6C3F_1_ Mice. VCU Protocol Number RF-SBM-28-1M-DW. VCU, Richmond, VA.
Van Sande, J., Massart, C., Beauwens, R., Schoutens, A., Costagliola, S., Dumont, J.E., and Wolff, J. (2003). Anion selectivity by the sodium iodide symporter. Endocrinology 144, 247–252.12488351
Watanabe, T., Abe, T., Satoh, M., Oda, Y., Takada, T., and Yanagihara, T. (1992). Two children with bromate intoxication due to ingestion of the second preparation for permanent hair waving. Acta Paediatr. Jpn. 34, 601–605.1285506
Williams, D.A. (1971). A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics 27, 103–117.5547548
Williams, D.A. (1972). The comparison of several dose levels with a zero dose control. Biometrics 28, 519–531.5037867
Williams, D.A. (1986). A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics 42, 183–186.3719054
Witt, K.L., Knapton, A., Wehr, C.M., Hook, G.J., Mirsalis, J., Shelby, M.D., and MacGregor, J.T. (2000). Micronucleated erythrocyte frequency in peripheral blood of B6C3F_1_ mice from short-term, prechronic, and chronic studies of the NTP Carcinogenesis Bioassay Program. Environ. Mol. Mutagen. 36, 163–194.11044899
Wolf, D.C., Crosby, L.M., George, M.H., Kilburn, S.R., Moore, T.M., Miller, R.T., and DeAngelo, A.B. (1998). Time- and dose-dependent development of potassium bromate-induced tumors in male Fischer 344 rats. Toxicol. Pathol. 26, 724–729.9864088
Wright, J.T., Hansen, L., Mahler, J., Szczesniak, C., and Spalding, J.W. (1995). Odontogenic tumours in the v-HA-ras (TG.AC) transgenic mouse. Arch. Oral Biol. 40, 631–638.7575235
Zeiger, E. (1998). Identification of rodent carcinogens and noncarcinogens using genetic toxicity tests: Premises, promises, and performance. Regul. Toxicol. Pharmacol. 28, 85–95.9927558
Zeiger, E., Anderson, B., Haworth, S., Lawlor, T., and Mortelmans, K. (1992). Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ. Mol. Mutagen. 19 (Suppl. 21), 2–141.1541260