# SUMMARY OF TECHNICAL REPORTS REVIEW SUBCOMMITTEE COMMENTS

On September 27, 2005, the draft Report on the toxicology and carcinogenicity studies of sodium bromate received public review by the National Toxicology Program’s Board of Scientific Counselors’ Technical Reports Review Subcommittee. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. M.J. Hooth, NIEHS, introduced the toxicology and carcinogenicity studies of sodium bromate in genetically modified mice by describing the uses of the chemical, the study design, and the effects of the chemical on survival, body weight, and nonneoplastic lesions in the animals. The proposed conclusions were no evidence of carcinogenic activity of sodium bromate in male or female p53 haploinsufficient mice.

Dr. Giesy, the first principal reviewer, said the studies were well designed and performed. He said he would like to see more discussion of the other non-cancer endpoints and possibly some discussion of the perceived utility of the model system.

Dr. Gasiewicz, the second principal reviewer, thought the proposed conclusions were appropriate. He noted that while the chemical was a carcinogen in other rodent models it was not in these models, and he suggested that be highlighted in the discussion. He emphasized the distinction between absolute and relative in descriptions of organ weights, and between statistical and biological significance in descriptions of lesion incidences.

Dr. Birt, the third principal reviewer, asked for better description of the origin of the animals and when in the process of rederiving the mouse strain these were obtained. Overall she agreed with the proposed conclusions.

Dr. Hooth noted that while thyroid gland or kidney neoplasms were not seen in these studies as they had been in the traditional 2-year bioassays, those sites were targets of toxicity in these shorter-term studies.

Dr. Roberts noted that different forms of conclusion statements are used for different model strains and that it would be useful to specify how these differ. Dr. C.J. Portier, NIEHS, explained that in the title of the reports the p53 model studies are described as carcinogenesis tests and the Tg.AC models are toxicity studies, with only the former using Levels of Evidence categories for conclusions.

Dr. R.J. Lorentzen, NCTR, suggested that the results of the studies in Tg.AC mice were not inconsistent with other studies performed on brominated compounds that showed kidney toxicity.

Dr. Gasiewicsz moved that the conclusions be accepted as written. Dr. Giesy seconded the motion. The motion was passed unanimously with six votes.