# RESULTS

## 26-Week Dermal Study in Tg.AC Hemizygous Mice

### Positive Control Tg.AC Hemizygous Mice

12-O-tetradecanoylphorbol-13-acetate (TPA) (1.25 µg) was dermally administered to groups of 15 male and 15 female Tg.AC hemizygous mice three times weekly for 26 weeks. Papillomas were first observed in week 8; all mice developed more than 20 papillomas each at the site of application (data not shown). This is consistent with historical rates found in other studies (Tennant et al., 2001).

### Survival

Estimates of 26-week survival probabilities for male and female mice are shown in Table 2. Survival of all dosed groups was similar to that of the vehicle control groups.

TABLE 2 Survival of Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Sodium Bromate

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Male
Animals initially in study | 15 | 15 | 15 | 15
Moribund | 2 | 1 | 0 | 0
Natural deaths | 1 | 3 | 2 | 0
Animals surviving to study termination | 12 | 11 | 13 | 15
Percent probability of survival at end of study^a^ | 80 | 73 | 87 | 100
Mean survival (days)^b^ | 163 | 162 | 171 | 181
Survival analysis^c^ | P=0.101N | P=0.987 | P=0.961N | P=0.224N
Female
Animals initially in study | 15 | 15 | 15 | 15
Moribund | 2 | 4 | 1 | 3
Natural deaths | 2 | 1 | 3 | 1
Animals surviving to study termination | 11 | 10 | 11 | 11
Percent probability of survival at end of study | 73 | 67 | 73 | 73
Mean survival (days) | 169 | 157 | 169 | 160
Survival analysis | P=1.000N | P=0.923 | P=1.000 | P=1.000

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice).

c The result of the life table trend test (Tarone, 1975) is in the vehicle control column, and the results of the life table pairwise comparisons (Cox, 1972) with the vehicle controls are in the dosed group columns. A negative trend or lower mortality in a dose group is indicated by N.

### Body Weights and Clinical Findings

Mean body weights of 256 mg/kg male mice were less than those of the vehicle controls during the last 3 weeks of the study; body weights of 64 and 128 mg/kg males and all dose groups of females were similar to those of the vehicle controls throughout the study (Figure 1 and Tables 3 and 4). Treatment-related clinical findings included increased observed papillomas in all dosed groups of males (vehicle control, 1/15; 64 mg/kg, 4/15; 128 mg/kg, 5/15; 256 mg/kg, 5/15) compared to the vehicle control group.

FIGURE 1 Growth Curves for Male and Female Tg.AC Hemizygous Mice Administered Sodium Bromate Dermally for 26 Weeks

TABLE 3 Mean Body Weights and Survival of Male Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Sodium Bromate

Weeks on Study | Vehicle Control | | 64 mg/kg | | | 128 ms/ks | | | 256 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 24.2 | 15 | 23.4 | 97 | 15 | 24.2 | 100 | 15 | 23.8 | 98 | 15
2 | 24.4 | 15 | 24.0 | 98 | 15 | 24.1 | 99 | 15 | 24.0 | 98 | 15
3 | 25.1 | 15 | 24.6 | 98 | 15 | 25.3 | 101 | 15 | 24.6 | 98 | 15
4 | 26.4 | 15 | 25.4 | 96 | 15 | 26.1 | 99 | 15 | 25.8 | 98 | 15
5 | 27.2 | 15 | 26.6 | 98 | 15 | 27.3 | 100 | 15 | 26.8 | 99 | 15
6 | 27.2 | 15 | 27.1 | 100 | 15 | 27.9 | 103 | 15 | 27.1 | 100 | 15
7 | 27.9 | 14 | 28.1 | 101 | 15 | 28.6 | 103 | 15 | 27.8 | 100 | 15
8 | 28.7 | 14 | 28.3 | 99 | 14 | 29.3 | 102 | 15 | 28.6 | 100 | 15
9 | 29.4 | 14 | 28.6 | 97 | 14 | 29.7 | 101 | 15 | 28.4 | 97 | 15
10 | 29.5 | 14 | 28.0 | 95 | 14 | 29.3 | 99 | 15 | 28.5 | 97 | 15
11 | 30.2 | 14 | 28.9 | 96 | 14 | 30.4 | 101 | 14 | 29.1 | 96 | 15
12 | 30.6 | 14 | 29.8 | 97 | 13 | 30.5 | 100 | 14 | 29.4 | 96 | 15
13 | 30.4 | 13 | 30.3 | 100 | 13 | 30.9 | 102 | 14 | 30.0 | 99 | 15
14 | 30.8 | 13 | 30.4 | 99 | 13 | 31.1 | 101 | 14 | 30.9 | 100 | 15
15 | 31.5 | 13 | 31.2 | 99 | 13 | 31.6 | 100 | 14 | 31.1 | 99 | 15
16 | 32.0 | 13 | 31.1 | 97 | 13 | 31.8 | 99 | 14 | 30.4 | 95 | 15
17 | 32.3 | 13 | 31.3 | 97 | 13 | 32.0 | 99 | 14 | 30.9 | 96 | 15
18 | 31.7 | 13 | 29.6 | 93 | 13 | 31.8 | 100 | 14 | 29.8 | 94 | 15
19 | 32.0 | 13 | 30.8 | 96 | 13 | 32.5 | 102 | 14 | 30.6 | 96 | 15
20 | 32.1 | 13 | 32.3 | 101 | 13 | 33.3 | 104 | 14 | 31.6 | 98 | 15
21 | 32.8 | 13 | 32.7 | 100 | 12 | 32.9 | 100 | 14 | 31.8 | 97 | 15
22 | 33.2 | 12 | 32.8 | 99 | 12 | 32.9 | 99 | 13 | 31.9 | 96 | 15
23 | 33.3 | 12 | 33.2 | 100 | 12 | 32.7 | 98 | 13 | 32.1 | 96 | 15
24 | 34.1 | 12 | 33.9 | 99 | 12 | 33.2 | 97 | 13 | 29.1 | 85 | 15
25 | 34.4 | 12 | 34.7 | 101 | 12 | 34.0 | 99 | 13 | 29.0 | 84 | 15
26 | 34.5 | 12 | 34.2 | 99 | 11 | 34.6 | 100 | 13 | 30.5 | 88 | 15
Mean for weeks
1–13 | 27.8 | | 27.2 | 98 | | 28.0 | 101 | | 27.2 | 98
14–26 | 32.7 | | 32.2 | 98 | | 32.6 | 100 | | 30.7 | 94

TABLE 4 Mean Body Weights and Survival of Female Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Sodium Bromate

Weeks on Study | Vehicle Control | | 64 mg/kg | | | 128 mg/kg | | | 256 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 19.4 | 15 | 19.4 | 100 | 15 | 19.5 | 101 | 15 | 19.3 | 100 | 15
2 | 19.6 | 15 | 19.5 | 100 | 15 | 19.7 | 101 | 15 | 19.3 | 99 | 15
3 | 20.6 | 15 | 20.9 | 102 | 15 | 21.1 | 102 | 15 | 20.7 | 101 | 15
4 | 21.3 | 15 | 21.9 | 103 | 15 | 21.9 | 103 | 15 | 21.8 | 102 | 15
5 | 21.5 | 15 | 22.8 | 106 | 15 | 22.5 | 105 | 15 | 22.4 | 104 | 15
6 | 22.2 | 15 | 22.8 | 103 | 15 | 23.1 | 104 | 15 | 22.7 | 102 | 15
7 | 23.4 | 15 | 23.5 | 100 | 15 | 23.4 | 100 | 15 | 23.5 | 100 | 15
8 | 23.2 | 15 | 23.8 | 103 | 15 | 24.0 | 103 | 15 | 24.1 | 104 | 15
9 | 23.7 | 15 | 24.3 | 103 | 15 | 24.2 | 102 | 15 | 24.6 | 104 | 15
10 | 23.7 | 14 | 23.7 | 100 | 15 | 23.8 | 100 | 15 | 24.7 | 104 | 15
11 | 24.5 | 14 | 23.6 | 96 | 14 | 24.5 | 100 | 15 | 24.4 | 100 | 14
12 | 24.4 | 14 | 23.9 | 98 | 13 | 24.7 | 101 | 15 | 25.3 | 104 | 14
13 | 24.5 | 14 | 24.5 | 100 | 12 | 24.9 | 102 | 15 | 24.9 | 102 | 14
14 | 24.6 | 14 | 25.6 | 104 | 12 | 25.3 | 103 | 15 | 25.6 | 104 | 14
15 | 24.8 | 14 | 25.2 | 102 | 12 | 25.1 | 101 | 15 | 25.6 | 103 | 13
16 | 25.4 | 14 | 25.3 | 100 | 12 | 24.7 | 97 | 15 | 25.7 | 101 | 13
17 | 25.3 | 14 | 25.6 | 101 | 12 | 25.3 | 100 | 14 | 25.6 | 101 | 13
18 | 25.8 | 14 | 25.7 | 100 | 12 | 24.6 | 95 | 14 | 25.3 | 98 | 11
19 | 26.0 | 14 | 25.9 | 100 | 12 | 25.8 | 99 | 14 | 26.3 | 101 | 11
20 | 25.5 | 14 | 26.1 | 102 | 12 | 25.2 | 99 | 14 | 26.1 | 102 | 11
21 | 25.7 | 14 | 26.4 | 103 | 12 | 26.4 | 103 | 12 | 26.0 | 101 | 11
22 | 26.4 | 13 | 26.9 | 102 | 12 | 26.7 | 101 | 11 | 26.4 | 100 | 11
23 | 26.1 | 13 | 26.6 | 102 | 11 | 26.6 | 102 | 11 | 27.1 | 104 | 11
24 | 26.7 | 12 | 26.7 | 100 | 11 | 26.3 | 99 | 11 | 27.3 | 102 | 11
25 | 27.4 | 11 | 27.8 | 102 | 10 | 27.2 | 99 | 11 | 27.8 | 102 | 11
26 | 27.1 | 11 | 27.6 | 102 | 10 | 25.7 | 95 | 11 | 28.2 | 104 | 11
Mean for weeks
1–13 | 22.5 | | 22.7 | 101 | | 22.9 | 102 | | 22.9 | 102
14–26 | 25.9 | | 26.3 | 101 | | 25.8 | 99 | | 26.4 | 102

### Hematology

Minimal (less than or equal to 8%) decreases in hematocrit and hemoglobin concentration values occurred in 128 mg/kg females and 256 mg/kg males and females (Tables 5 and E1); a minimal (7%) decrease in erythrocyte count also occurred in 256 mg/kg males. These decreases in erythron were accompanied by minimal (less than or equal to 6%) decreases in mean cell hemoglobin and mean cell hemoglobin concentration values, primarily in the females; the mean cell volume was unaffected. The erythron decrease was also accompanied by an apparent regenerative-type response indicated by an approximate 45% increase in reticulocyte counts in 128 mg/kg females and 256 mg/kg males and females.

TABLE 5 Selected Hematology Data for Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Sodium Bromate^a^

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Male
n | 12 | 10 | 13 | 12
Hematocrit (%) | 42.9 ± 0.5 | 41.4 ± 0.7 | 41.9 ± 0.7 | 41.0 ± 0.6
Hemoglobin (g/dL) | 13.9 ± 0.2 | 13.2 ± 0.2 | 13.4 ± 0.2 | 13.0 ± 0.2^**^
Erythrocytes (10^6^/μL) | 9.91 ± 0.15 | 9.47 ± 0.17 | 9.65 ± 0.18 | 9.29 ± 0.18^*^
Reticulocytes (10^6^/μL) | 0.15 ± 0.02 | 0.19 ± 0.02 | 0.19 ± 0.01 | 0.22 ± 0.02^*^
Mean cell volume (fL) | 43.3 ± 0.4 | 43.8 ± 0.2 | 43.4 ± 0.3 | 44.2 ± 0.3
Mean cell hemoglobin (pg) | 14.0 ± 0.2 | 14.0 ± 0.1 | 13.9 ± 0.1 | 14.0 ± 0.2
Mean cell hemoglobin concentration (g/dL) | 32.3 ± 0.1 | 32.0 ± 0.1 | 32.1 ± 0.2 | 31.7 ± 0.3^*^
Female
n | 10 | 10 | 11 | 11
Hematocrit (%) | 43.4 ± 0.5 | 42.6 ± 0.5 | 41.0 ± 0.8^*^ | 41.1 ± 0.5^**^
Hemoglobin (g/dL) | 14.3 ± 0.1 | 13.8 ± 0.2 | 13.1 ± 0.3^**^ | 13.1 ± 0.1^**^
Erythrocytes (10^6^/μL) | 9.84 ± 0.19 | 9.55 ± 0.13 | 9.45 ± 0.31 | 9.67 ± 0.25
Reticulocytes (10^6^/μL) | 0.15 ± 0.01 | 0.19 ± 0.01 | 0.21 ± 0.02^*^ | 0.21 ± 0.02^*^
Mean cell volume (fL) | 44.1 ± 0.5 | 44.6 ± 0.2 | 43.6 ± 0.6 | 42.7 ± 0.7
Mean cell hemoglobin (pg) | 14.5 ± 0.2 | 14.5 ± 0.1 | 14.0 ± 0.2^*^ | 13.6 ± 0.2^**^
Mean cell hemoglobin concentration (g/dL) | 32.9 ± 0.1 | 32.5 ± 0.1^**^ | 32.0 ± 0.1^**^ | 31.8 ± 0.2^**^

* Significantly different (P≤0.05) from the vehicle control group by Dunn’s or Shirley’s test

** P≤0.01

a Mean ± standard error. Statistical tests were performed on unrounded data.

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the skin, thyroid gland, kidney, and spleen. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables A1, A2, A3, and A4.

Skin: Dermal administration of sodium bromate for 26 weeks resulted in no squamous cell papillomas at the site of application in males or females and no significant treatment-related changes in the incidences of neoplasms or nonneoplastic lesions of the skin of male mice. Combined incidences of multiple and single squamous cell papillomas of the skin were slightly increased in the 256 mg/kg group of female mice (vehicle control, 5/15; 64 mg/kg, 3/15; 128 mg/kg, 4/15; 256 mg/kg, 9/15; Table A3). The increase was not significant (by the Fisher exact test). Characteristic squamous cell papillomas were pedunculated skin masses consisting of multiple finger-like projections composed of branching fibrous tissue cores covered by hyperplastic epithelium. Other solid skin masses composed of stratified squamous epithelium without projections were still considered papillomas.

Thyroid Gland: Significantly increased treatment-related changes were observed in thyroid glands of both male and female mice (Tables 6, A2, and A4). Changes were more frequent and severe in females. The incidences of follicular cell hypertrophy were significantly increased in all dosed groups of males and females. Follicular hypertrophy was characterized by an increase in the size of cells lining follicles. In animals from the higher dose groups, the follicles became quite small or were completely obliterated by large hypertrophied follicular lining cells. The incidences of follicular secretory depletion were significantly increased in 128 and 256 mg/kg females with a smaller increase in 256 mg/kg males and 64 mg/kg females. The diagnosis of follicular secretory depletion was based primarily on qualitative changes in the colloid rather than the quantity of colloid within follicles. Affected follicles had pale staining colloid that contained basophilic concretion-like structures and were dilated with thinning of the follicular epithelium. These follicles tended to have a more angular appearance than normal round follicles. In animals from the higher dose groups, the pale staining colloid became vacuolated or granular or contained a thickened floccular material. The incidences of lymphocyte cellular infiltrates were significantly increased in 64 and 256 mg/kg females. Lymphocytic infiltration consisted of aggregates of varying numbers of lymphocytes within the stroma among follicles.

TABLE 6 Incidences of Nonneoplastic Lesions of the Thyroid Gland in Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Sodium Bromate

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Male
Number Examined Microscopically | 15 | 15 | 15 | 15
Follicular Cell, Hypertrophy^a^ | 0 | 7^**^ (1.0)^b^ | 10^**^ (1.3) | 14^**^ (1.4)
Follicle, Depletion Secretory | 7 (1.0) | 4 (1.0) | 5 (1.0) | 11 (1.1)
Female
Number Examined Microscopically | 15 | 15 | 15 | 15
Follicular Cell, Hypertrophy | 1 (1.0) | 9^**^ (1.0) | 12^**^ (1.9) | 13^**^ (2.8)
Follicle, Depletion Secretory | 6 (1.2) | 11 (1.2) | 13^**^ (1.5) | 14^**^ (2.6)
Infiltration Cellular, Lymphocyte | 0 | 6^**^ (1.0) | 3 (1.0) | 12^**^ (1.3)

** Significantly different (P≤0.01) from the vehicle control group by the Fisher exact test

a Number of animals with lesion

b Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

Kidney: Relative kidney weights were significantly increased in 256 mg/kg males compared to the vehicle controls (Table F1). The incidences of nephropathy were significantly increased in 128 mg/kg males and 256 mg/kg males and females (Tables 7, A2, and A4). These lesions were usually minimal in severity. Nephropathy included unequivocal tubular basophilia (regeneration), tubular dilatation, proteinaceous casts, basement membrane thickening and interstitial inflammation, as well as increased mitotic figures and nuclear pleomorphism.

Spleen: Hematopoietic cell proliferation increased with increasing dose in female mice. Significant increases occurred in 128 and 256 mg/kg females (Tables 7 and A4).

TABLE 7 Incidences of Selected Nonneoplastic Lesions in Tg.AC Hemizygous Mice in the 26-Week Dermal Study of Sodium Bromate

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Male
Kidney^a^ | 15 | 15 | 15 | 15
Nephropathy^b^ | 8 (1.0)^c^ | 8 (1.1) | 14^*^ (1.0) | 14^*^ (1.1)
Female
Kidney | 15 | 15 | 15 | 15
Nephropathy | 8 (1.0) | 7 (1.0) | 13 (1.0) | 15^**^ (1.0)
Spleen | 15 | 15 | 15 | 15
Hematopoietic Cell Proliferation | 3 (1.7) | 5 (1.4) | 9^*^ (1.9) | 10^*^ (2.1)

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test

** P≤0.01

a Number of animals with tissue examined microscopically

b Number of animals with lesion

c Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

## 39-Week Dermal Study in Tg.AC Hemizygous Mice

### Survival

Estimates of 39-week survival probabilities for male and female mice are shown in Table 8. Survival of all dosed groups was similar to that of the vehicle control groups.

### Body Weights and Clinical Findings

Mean body weights of 128 mg/kg male mice were less than those of the vehicle controls at the end of the study (Figure 2, Tables 9 and 10), and those of 256 mg/kg males were generally less after week 28. Mean body weights of 64 and 128 mg/kg females were generally less than those of the vehicle controls after week 12, and those of 256 mg/kg females were less after week 18. No clinical findings were attributed to sodium bromate administration.

TABLE 8 Survival of Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Sodium Bromate

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Male
Animals initially in study | 10 | 10 | 10 | 10
Moribund | 1 | 0 | 0 | 2
Natural deaths | 1 | 2 | 2 | 0
Animals surviving to study termination | 8 | 8 | 8 | 8
Percent probability of survival at end of study^a^ | 80 | 80 | 80 | 80
Mean survival (days)^b^ | 253 | 257 | 265 | 247
Survival analysis^c^ | P=1.000N | P=1.000N | P=1.000N | P=1.000N
Female
Animals initially in study | 10 | 10 | 10 | 10
Missing^d^ | 1 | 0 | 0 | 0
Moribund | 1 | 1 | 2 | 1
Natural deaths | 1 | 2 | 0 | 1
Animals surviving to study termination | 7 | 7 | 8 | 8
Percent probability of survival at end of study | 78 | 70 | 80 | 80
Mean survival (days) | 264 | 226 | 252 | 265
Survival analysis | P=0.891N | P=0.929 | P=1.000N | P=1.000N

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice).

c The result of the life table trend test (Tarone, 1975) is in the vehicle control column, and the results of the life table pairwise comparisons (Cox, 1972) with the vehicle controls are in the dosed group columns. A negative trend or lower mortality in a dose group is indicated by N.

d Censored from survival analysis

FIGURE 2 Growth Curves for Male and Female Tg.AC Hemizygous Mice Administered Sodium Bromate Dermally for 39 Weeks

TABLE 9 Mean Body Weights and Survival of Male Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Sodium Bromate

Weeks on Study | Vehicle Control | | 64 mg/kg | | | 128 mg/kg | | | 256 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 24.1 | 10 | 24.1 | 100 | 10 | 24.1 | 100 | 10 | 24.0 | 100 | 10
2 | 24.4 | 10 | 24.5 | 100 | 10 | 24.5 | 100 | 10 | 24.2 | 99 | 10
3 | 25.2 | 10 | 25.5 | 101 | 10 | 25.6 | 102 | 10 | 25.3 | 100 | 10
4 | 26.2 | 10 | 26.0 | 99 | 10 | 26.3 | 100 | 10 | 26.4 | 101 | 10
5 | 27.2 | 10 | 26.7 | 98 | 10 | 27.1 | 100 | 10 | 27.6 | 102 | 10
6 | 27.9 | 10 | 27.7 | 99 | 10 | 27.5 | 99 | 10 | 28.3 | 101 | 10
7 | 28.7 | 10 | 28.7 | 100 | 10 | 29.1 | 101 | 10 | 29.2 | 102 | 10
8 | 29.1 | 10 | 28.8 | 99 | 10 | 29.3 | 101 | 10 | 29.3 | 101 | 10
9 | 29.0 | 10 | 29.2 | 101 | 10 | 29.3 | 101 | 10 | 29.1 | 100 | 10
10 | 29.0 | 10 | 29.1 | 100 | 10 | 27.8 | 96 | 10 | 29.5 | 102 | 10
11 | 29.9 | 10 | 29.4 | 98 | 10 | 29.8 | 100 | 10 | 29.9 | 100 | 9
12 | 29.9 | 10 | 29.8 | 100 | 10 | 29.7 | 99 | 10 | 30.4 | 102 | 9
13 | 30.5 | 10 | 29.9 | 98 | 10 | 30.2 | 99 | 10 | 30.3 | 99 | 9
14 | 30.4 | 10 | 30.8 | 101 | 10 | 31.0 | 102 | 10 | 30.7 | 101 | 9
15 | 31.3 | 10 | 31.0 | 99 | 10 | 31.0 | 99 | 10 | 31.3 | 100 | 9
16 | 31.4 | 10 | 31.0 | 99 | 10 | 31.5 | 100 | 10 | 31.6 | 101 | 9
17 | 32.0 | 10 | 31.6 | 99 | 10 | 31.7 | 99 | 10 | 31.4 | 98 | 9
18 | 31.4 | 10 | 32.1 | 102 | 10 | 31.9 | 102 | 10 | 31.7 | 101 | 9
19 | 30.2 | 10 | 32.4 | 107 | 10 | 31.1 | 103 | 10 | 31.8 | 105 | 9
20 | 32.3 | 10 | 32.5 | 101 | 10 | 31.1 | 96 | 10 | 32.8 | 102 | 9
21 | 31.5 | 9 | 32.9 | 104 | 9 | 31.5 | 100 | 10 | 32.4 | 103 | 9
22 | 32.2 | 9 | 32.5 | 101 | 9 | 32.3 | 100 | 10 | 31.8 | 99 | 9
23 | 32.9 | 9 | 32.9 | 100 | 9 | 31.7 | 96 | 10 | 32.0 | 97 | 9
24 | 32.3 | 9 | 33.8 | 105 | 9 | 33.0 | 102 | 10 | 33.0 | 102 | 9
25 | 33.8 | 9 | 33.6 | 99 | 9 | 33.5 | 99 | 10 | 33.7 | 100 | 9
26 | 34.9 | 9 | 34.2 | 98 | 9 | 33.9 | 97 | 10 | 33.1 | 95 | 9
27 | 35.2 | 9 | 34.9 | 99 | 9 | 34.3 | 97 | 10 | 33.7 | 96 | 9
28 | 35.5 | 9 | 34.4 | 97 | 9 | 33.6 | 95 | 10 | 33.7 | 95 | 9
29 | 35.8 | 9 | 35.2 | 98 | 9 | 35.2 | 98 | 10 | 32.8 | 92 | 9
30 | 34.6 | 9 | 33.7 | 97 | 9 | 35.3 | 102 | 10 | 33.5 | 97 | 9
31 | 36.5 | 9 | 35.5 | 97 | 9 | 35.5 | 97 | 10 | 33.8 | 93 | 9
32 | 36.5 | 8 | 36.2 | 99 | 9 | 36.0 | 99 | 10 | 33.6 | 92 | 9
33 | 36.9 | 8 | 35.9 | 97 | 9 | 35.9 | 97 | 9 | 34.3 | 93 | 8
34 | 37.0 | 8 | 36.1 | 98 | 9 | 36.3 | 98 | 9 | 34.0 | 92 | 8
35 | 36.5 | 8 | 36.1 | 99 | 9 | 35.1 | 96 | 9 | 34.0 | 93 | 8
36 | 35.7 | 8 | 36.4 | 102 | 9 | 34.9 | 98 | 9 | 34.6 | 97 | 8
37 | 36.4 | 8 | 36.3 | 100 | 8 | 36.6 | 101 | 8 | 35.1 | 96 | 8
38 | 36.4 | 8 | 35.5 | 98 | 8 | 33.7 | 93 | 8 | 34.0 | 93 | 8
39 | 36.1 | 8 | 34.9 | 97 | 8 | 33.7 | 93 | 8 | 33.4 | 93 | 8
Mean for weeks
1–13 | 27.8 | | 27.6 | 100 | | 27.7 | 100 | | 28.0 | 101
14–39 | 34.1 | | 33.9 | 100 | | 33.5 | 99 | | 33.0 | 97

TABLE 10 Mean Body Weights and Survival of Female Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Sodium Bromate

Weeks on Study | Vehicle Control | | 64 mg/kg | | | 128 mg/kg | | | 256 mg/kg
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 19.4 | 10 | 19.7 | 102 | 10 | 19.1 | 99 | 10 | 19.4 | 100 | 10
2 | 19.6 | 10 | 20.0 | 102 | 10 | 19.8 | 101 | 10 | 19.2 | 98 | 10
3 | 21.3 | 10 | 20.5 | 96 | 10 | 20.9 | 98 | 10 | 21.0 | 99 | 10
4 | 22.4 | 10 | 22.6 | 101 | 10 | 22.1 | 99 | 10 | 22.3 | 100 | 10
5 | 23.4 | 9 | 23.2 | 99 | 10 | 23.0 | 98 | 10 | 22.7 | 97 | 10
6 | 23.6 | 9 | 23.2 | 98 | 10 | 22.8 | 97 | 10 | 22.8 | 97 | 10
7 | 23.6 | 9 | 23.4 | 99 | 10 | 23.1 | 98 | 10 | 22.8 | 97 | 10
8 | 24.3 | 9 | 23.7 | 98 | 10 | 23.2 | 96 | 10 | 23.7 | 98 | 10
9 | 24.6 | 9 | 23.9 | 97 | 10 | 23.6 | 96 | 10 | 23.7 | 96 | 10
10 | 24.3 | 9 | 22.8 | 94 | 9 | 23.2 | 96 | 10 | 23.8 | 98 | 10
11 | 25.5 | 9 | 24.1 | 95 | 9 | 24.0 | 94 | 10 | 24.5 | 96 | 10
12 | 25.6 | 9 | 24.6 | 96 | 9 | 24.3 | 95 | 10 | 25.2 | 98 | 10
13 | 26.1 | 9 | 24.9 | 95 | 9 | 23.8 | 91 | 10 | 25.3 | 97 | 10
14 | 27.1 | 9 | 25.2 | 93 | 9 | 23.9 | 88 | 10 | 25.3 | 93 | 10
15 | 26.9 | 9 | 25.7 | 96 | 9 | 24.1 | 90 | 10 | 26.0 | 97 | 10
16 | 27.2 | 9 | 25.6 | 94 | 9 | 23.7 | 87 | 10 | 25.9 | 95 | 10
17 | 28.0 | 9 | 25.9 | 93 | 9 | 24.7 | 88 | 10 | 26.9 | 96 | 10
18 | 28.6 | 9 | 25.1 | 88 | 9 | 23.9 | 84 | 10 | 27.1 | 95 | 10
19 | 29.2 | 9 | 26.0 | 89 | 9 | 24.2 | 83 | 10 | 26.3 | 90 | 10
20 | 30.1 | 9 | 26.8 | 89 | 9 | 25.7 | 85 | 9 | 27.3 | 91 | 10
21 | 30.0 | 9 | 25.6 | 85 | 9 | 24.9 | 83 | 9 | 27.0 | 90 | 10
22 | 29.6 | 9 | 25.8 | 87 | 7 | 25.3 | 86 | 9 | 27.1 | 92 | 10
23 | 29.7 | 9 | 26.8 | 90 | 7 | 24.9 | 84 | 9 | 27.6 | 93 | 10
24 | 30.8 | 9 | 25.9 | 84 | 7 | 25.2 | 82 | 9 | 28.5 | 93 | 10
25 | 31.6 | 9 | 25.7 | 81 | 7 | 25.7 | 81 | 9 | 28.6 | 91 | 10
26 | 31.3 | 9 | 26.1 | 83 | 7 | 25.3 | 81 | 9 | 27.8 | 89 | 10
27 | 31.9 | 9 | 27.0 | 85 | 7 | 26.6 | 83 | 9 | 28.5 | 89 | 10
28 | 32.2 | 9 | 26.8 | 83 | 7 | 26.0 | 81 | 9 | 28.9 | 90 | 10
29 | 33.2 | 9 | 27.4 | 83 | 7 | 26.7 | 80 | 9 | 29.6 | 89 | 10
30 | 33.3 | 9 | 27.3 | 82 | 7 | 25.9 | 78 | 9 | 29.9 | 90 | 10
31 | 33.0 | 9 | 27.4 | 83 | 7 | 27.8 | 84 | 9 | 30.3 | 92 | 10
32 | 34.7 | 8 | 28.6 | 82 | 7 | 27.0 | 78 | 9 | 30.6 | 88 | 9
33 | 34.4 | 8 | 28.3 | 82 | 7 | 28.0 | 81 | 8 | 30.6 | 89 | 9
34 | 34.1 | 8 | 27.9 | 82 | 7 | 27.5 | 81 | 8 | 30.0 | 88 | 9
35 | 33.2 | 8 | 28.6 | 86 | 7 | 27.6 | 83 | 8 | 28.5 | 86 | 9
36 | 32.6 | 8 | 28.0 | 86 | 7 | 28.4 | 87 | 8 | 28.3 | 87 | 9
37 | 33.5 | 7 | 28.2 | 84 | 7 | 29.2 | 87 | 8 | 28.4 | 85 | 9
38 | 32.0 | 7 | 28.7 | 90 | 7 | 27.9 | 87 | 8 | 28.3 | 88 | 8
39 | 33.2 | 7 | 28.5 | 86 | 7 | 28.0 | 84 | 8 | 28.9 | 87 | 8
Mean for weeks
1–13 | 23.4 | | 22.8 | 98 | | 22.5 | 97 | | 22.8 | 98
14–39 | 31.2 | | 26.9 | 86 | | 26.1 | 84 | | 28.2 | 90

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the skin, forestomach, thyroid gland, kidney, and testes. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables A5, A6, A7, and A8.

Skin: Dermal administration of sodium bromate for 39 weeks resulted in no significant treatment-related increases in neoplasms or nonneoplastic lesions of the skin of either male or female Tg.AC hemizygous mice (Tables A5, A6, A7, and A8).

Forestomach: Combined incidences of multiple and single squamous cell papillomas were increased in the 128 and 256 mg/kg groups of female mice (vehicle control, 2/9; 64 mg/kg, 2/10; 128 mg/kg, 7/10; 256 mg/kg, 4/10; Table A7); the increases were not significant. Forestomach neoplasms did not occur in male mice (Table A5). Squamous cell papillomas of the forestomach were similar in microscopic appearance to those described in the skin at 26 weeks.

Thyroid Gland: Significantly increased treatment-related changes were observed in thyroid glands of male and female mice (Tables 11, A6, and A8). As with the 26-week study, changes were more frequent and severe in females. The microscopic changes were similar to those observed at 26 weeks. The incidences of follicular cell hypertrophy were significantly increased in all dosed groups of males and females; and the severities were increased in females (Tables 11, A6, and A8). Incidences of lymphocyte cellular infiltrates increased with increasing dose in females; and the incidences were significantly increased in the 128 and 256 mg/kg groups (Tables 11 and A8). The incidence of follicular secretory depletion was significantly increased in 128 and 256 mg/kg females, and the severity of this lesion increased with increasing dose.

Kidney: Absolute kidney weights were significantly decreased in 256 mg/kg females (Table F2). Relative kidney weights were significantly increased in all dosed groups of males compared to the vehicle control group.

The incidence of nephropathy was significantly increased in 256 mg/kg females (Tables 11 and A8). The lesions were minimal to mild in severity. The incidence of renal cell hypertrophy was slightly increased in 256 mg/kg females (Tables 11 and A8). Renal tubule hypertrophy referred to tubules having palely stained enlarged epithelial cells that did not have features suggesting degeneration.

Testes: Absolute testis weights were significantly decreased in 256 mg/kg males. The incidences of germinal epithelium degeneration increased with increasing dose, and the increase was significant in 256 mg/kg males (Tables 11 and A6). Microscopically, the degeneration consisted of vacuolar changes with partial to complete loss of the germinal epithelium within seminiferous tubules leaving only Sertoli cells and resulting in shrinkage and atrophy of the affected tubules.

TABLE 11 Incidences of Selected Nonneoplastic Lesions in Tg.AC Hemizygous Mice in the 39-Week Dermal Study of Sodium Bromate

| Vehicle Control | 64 mg/kg | 128 mg/kg | 256 mg/kg
Male
Thyroid Gland^a^ | 10 | 10 | 10 | 10
Follicular Cell, Hypertrophy^b^ | 0 | 9^**^ (1.0)^c^ | 8^**^ (1.5) | 8^**^ (1.9)
Testes | 10 | 10 | 10 | 10
Germinal Epithelium, Degeneration | 1 (3.0) | 2 (1.5) | 3 (3.0) | 6^*^ (2.8)
Female
Thyroid Gland | 9 | 10 | 10 | 10
Follicular Cell, Hypertrophy | 1 (1.0) | 9^**^ (1.6) | 9^**^ (2.9) | 10^**^ (3.3)
Infiltration Cellular, Lymphocyte | 0 | 2 (1.5) | 5^*^ (1.2) | 10^**^ (1.4)
Follicle, Depletion Secretory | 5 (1.2) | 8 (1.5) | 10^*^ (2.7) | 10^*^ (3.5)
Kidney | 9 | 10 | 10 | 10
Nephropathy | 5 (1.0) | 6 (1.0) | 8 (1.0) | 10^*^ (1.3)
Renal Tubule, Hypertrophy | 0 | 0 | 0 | 4 (1.0)

* Significantly different (P≤0.05) from the vehicle control group by the Fisher exact test

** P≤0.01

a Number of animals with tissue examined microscopically

b Number of animals with lesion

c Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

## 27-Week Drinking Water Study in Tg.AC Hemizygous Mice

### Positive Control Tg.AC Hemizygous Mice

12-O-tetradecanoylphorbol-13-acetate (TPA) (1.25 µg) was administered dermally to groups of 15 males and 15 females three times weekly for 26 weeks. Papillomas were first observed at week 11 for males and week 9 for females; 80% of males and females developed more than 20 papillomas each before scheduled study termination (data not shown). This is consistent with historical rates found in other studies (Tennant et al., 2001).

### Survival

Estimates of 27-week survival probabilities for male and female mice are shown in Table 12. Survival of all exposed groups was similar to that of the control groups.

### Body Weights and Clinical Findings

Mean body weights of 800 mg/L males were less than those of the controls after week 5. Mean body weights of 400 mg/L males and 800 mg/L females were less than those of the control groups after week 9 (Figure 3; Tables 13 and 14). Water consumption by exposed mice was generally similar to that by controls throughout the study (Tables H1 and H2). Drinking water concentrations of 80, 400, and 800 mg/L resulted in average daily doses of approximately 13, 63, and 129 mg sodium bromate/kg body weight to male mice and 15, 72, and 148 mg/kg to female mice. No clinical findings were attributed to the administration of sodium bromate.

TABLE 12 Survival of Tg.AC Hemizygous Mice in the 27-Week Drinking Water Study of Sodium Bromate

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Male
Animals initially in study | 15 | 15 | 15 | 15
Moribund | 0 | 0 | 1 | 0
Natural deaths | 2 | 2 | 0 | 1
Animals surviving to study termination | 13 | 13 | 14 | 14
Percent probability of survival at end of study^a^ | 87 | 87 | 93 | 93
Mean survival (days)^b^ | 172 | 181 | 180 | 181
Survival analysis^c^ | P=0.620N | P=1.000N | P=0.984N | P=0.984N
Female
Animals initially in study | 15 | 15 | 15 | 15
Moribund | 2 | 1 | 0 | 0
Natural deaths | 3 | 5 | 5 | 3
Animals surviving to study termination | 10 | 9 | 10 | 12
Percent probability of survival at end of study | 67 | 60 | 67 | 80
Mean survival (days) | 159 | 149 | 164 | 159
Survival analysis | P=0.414N | P=0.905 | P=1.000N | P=0.728N

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice).

c The result of the life table trend test (Tarone, 1975) is in the control column, and the results of the life table pairwise comparisons (Cox, 1972) with the controls are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

FIGURE 3 Growth Curves for Male and Female Tg.AC Hemizygous Mice Exposed to Sodium Bromate in Drinking Water for 27 Weeks

TABLE 13 Mean Body Weights and Survival of Male Tg.AC Hemizygous Mice in the 27-Week Drinking Water Study of Sodium Bromate

Weeks on Study | 0 mg/L | | 80 mg/L | | | 400 mg/L | | | 800 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 23.6 | 15 | 23.9 | 101 | 15 | 23.6 | 100 | 15 | 23.8 | 101 | 15
2 | 24.1 | 15 | 24.8 | 103 | 15 | 24.0 | 100 | 15 | 23.9 | 99 | 15
3 | 26.2 | 15 | 26.4 | 101 | 15 | 26.0 | 99 | 15 | 25.3 | 97 | 15
4 | 27.6 | 15 | 27.9 | 101 | 15 | 27.4 | 99 | 15 | 26.9 | 98 | 15
5 | 28.3 | 15 | 29.1 | 103 | 15 | 28.6 | 101 | 15 | 27.4 | 97 | 15
6 | 29.7 | 14 | 30.0 | 101 | 15 | 29.3 | 99 | 15 | 28.0 | 94 | 15
7 | 30.8 | 14 | 30.7 | 100 | 15 | 29.9 | 97 | 15 | 28.6 | 93 | 15
8 | 31.7 | 14 | 31.3 | 99 | 15 | 30.4 | 96 | 15 | 28.7 | 91 | 15
9 | 32.6 | 14 | 32.4 | 99 | 15 | 31.4 | 96 | 15 | 29.6 | 91 | 15
10 | 33.3 | 14 | 33.0 | 99 | 15 | 31.7 | 95 | 15 | 29.2 | 88 | 15
11 | 34.9 | 14 | 34.5 | 99 | 15 | 32.3 | 93 | 15 | 30.1 | 86 | 15
12 | 35.9 | 14 | 35.0 | 98 | 15 | 33.1 | 92 | 15 | 30.8 | 86 | 15
13 | 36.5 | 14 | 35.9 | 98 | 15 | 34.2 | 94 | 15 | 31.1 | 85 | 15
14 | 36.5 | 14 | 36.2 | 99 | 15 | 33.6 | 92 | 15 | 30.6 | 84 | 15
15 | 36.3 | 14 | 35.8 | 99 | 15 | 35.0 | 96 | 15 | 31.7 | 87 | 15
16 | 35.7 | 14 | 35.3 | 99 | 15 | 34.1 | 96 | 15 | 31.7 | 89 | 15
17 | 35.8 | 14 | 35.6 | 99 | 15 | 33.4 | 93 | 15 | 31.0 | 87 | 15
18 | 36.2 | 14 | 35.8 | 99 | 15 | 33.0 | 91 | 15 | 30.8 | 85 | 15
19 | 36.2 | 14 | 35.4 | 98 | 15 | 33.3 | 92 | 15 | 30.6 | 85 | 15
20 | 36.4 | 14 | 36.0 | 99 | 15 | 33.1 | 91 | 15 | 31.2 | 86 | 15
21 | 36.6 | 14 | 36.6 | 100 | 15 | 33.6 | 92 | 15 | 31.4 | 86 | 15
22 | 37.1 | 14 | 37.0 | 100 | 15 | 33.9 | 91 | 14 | 31.5 | 85 | 15
23 | 36.4 | 14 | 37.2 | 102 | 14 | 33.3 | 92 | 14 | 30.9 | 85 | 15
24 | 37.0 | 14 | 37.6 | 102 | 14 | 34.3 | 93 | 14 | 31.1 | 84 | 14
25 | 36.2 | 14 | 37.6 | 104 | 14 | 33.9 | 94 | 14 | 31.7 | 88 | 14
26 | 38.0 | 13 | 37.1 | 98 | 14 | 34.0 | 90 | 14 | 32.1 | 85 | 14
Mean for weeks
1–13 | 30.4 | | 30.4 | 100 | | 29.4 | 97 | | 28.0 | 93
14–26 | 36.5 | | 36.4 | 100 | | 33.7 | 93 | | 31.3 | 86

TABLE 14 Mean Body Weights and Survival of Female Tg.AC Hemizygous Mice in the 27-Week Drinking Water Study of Sodium Bromate

Weeks on Study | 0 mg/L | | 80 mg/L | | | 400 mg/L | | | 800 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 19.2 | 15 | 19.4 | 101 | 15 | 19.7 | 103 | 15 | 19.8 | 103 | 15
2 | 19.6 | 15 | 20.1 | 103 | 15 | 20.0 | 102 | 15 | 19.2 | 98 | 15
3 | 20.3 | 15 | 21.5 | 106 | 15 | 21.4 | 105 | 15 | 21.0 | 103 | 14
4 | 22.6 | 15 | 22.9 | 101 | 15 | 23.2 | 103 | 15 | 22.4 | 99 | 14
5 | 23.5 | 14 | 23.6 | 100 | 15 | 24.1 | 103 | 14 | 22.8 | 97 | 13
6 | 23.8 | 14 | 24.0 | 101 | 15 | 23.8 | 100 | 14 | 22.4 | 94 | 13
7 | 25.0 | 14 | 24.5 | 98 | 15 | 24.5 | 98 | 14 | 23.7 | 95 | 13
8 | 25.3 | 13 | 25.3 | 100 | 14 | 25.1 | 99 | 14 | 24.1 | 95 | 13
9 | 26.4 | 13 | 26.0 | 99 | 13 | 25.8 | 98 | 14 | 25.0 | 95 | 13
10 | 27.6 | 13 | 26.4 | 96 | 13 | 26.2 | 95 | 14 | 24.3 | 88 | 13
11 | 28.0 | 13 | 26.2 | 94 | 13 | 26.0 | 93 | 14 | 25.5 | 91 | 13
12 | 28.4 | 13 | 27.2 | 96 | 13 | 26.7 | 94 | 14 | 25.5 | 90 | 13
13 | 28.3 | 13 | 27.6 | 98 | 13 | 26.9 | 95 | 14 | 25.5 | 90 | 13
14 | 28.4 | 13 | 27.7 | 98 | 12 | 27.3 | 96 | 13 | 25.6 | 90 | 13
15 | 28.9 | 13 | 27.4 | 95 | 12 | 27.7 | 96 | 13 | 26.0 | 90 | 13
16 | 28.7 | 13 | 27.7 | 97 | 11 | 27.2 | 95 | 13 | 26.2 | 91 | 13
17 | 29.0 | 13 | 27.7 | 96 | 11 | 27.2 | 94 | 13 | 25.2 | 87 | 13
18 | 28.7 | 13 | 27.4 | 96 | 11 | 27.8 | 97 | 13 | 26.1 | 91 | 13
19 | 28.2 | 12 | 28.0 | 99 | 11 | 28.9 | 103 | 13 | 25.4 | 90 | 13
20 | 29.1 | 12 | 29.0 | 100 | 11 | 29.2 | 100 | 13 | 25.8 | 89 | 13
21 | 29.6 | 12 | 29.3 | 99 | 10 | 29.5 | 100 | 13 | 25.8 | 87 | 13
22 | 30.9 | 12 | 29.7 | 96 | 9 | 30.3 | 98 | 13 | 26.6 | 86 | 12
23 | 29.8 | 12 | 29.4 | 99 | 9 | 30.1 | 101 | 12 | 26.6 | 89 | 12
24 | 30.6 | 12 | 29.4 | 96 | 9 | 31.0 | 101 | 11 | 26.2 | 86 | 12
25 | 31.4 | 12 | 29.8 | 95 | 9 | 31.2 | 99 | 11 | 26.6 | 85 | 12
26 | 31.2 | 11 | 30.5 | 98 | 9 | 31.8 | 102 | 11 | 26.5 | 85 | 12
Mean for weeks
1–13 | 24.5 | | 24.2 | 99 | | 24.1 | 99 | | 23.2 | 95
14–26 | 29.6 | | 28.7 | 97 | | 29.2 | 99 | | 26.0 | 88

### Hematology

In the drinking water study, the erythron demonstrated effects that were similar to those observed in the dermal study. There were minimal (less than or equal to 10%) decreases in hematocrit, hemoglobin concentration, and erythrocyte count values that occurred primarily in 400 and 800 mg/L females (Tables 15 and E2). There were also decreases of 5% or less in the mean cell hemoglobin and mean cell hemoglobin concentration values, but these occurred primarily in exposed males. Reticulocyte counts were increased in 400 mg/L males (35%) and 800 mg/L males (67%) and females (130%).

TABLE 15 Selected Hematology Data for Tg.AC Hemizygous Mice in the 27-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Male
n | 12 | 13 | 13 | 14
Hematocrit (%) | 40.8 ± 0.5 | 41.0 ± 0.4 | 40.1 ± 0.4 | 41.7 ± 0.4
Hemoglobin (g/dL) | 13.3 ± 0.2 | 13.2 ± 0.1 | 12.8 ± 0.2^*^ | 13.0 ± 0.2
Erythrocytes (10^6^/μL) | 9.31 ± 0.15 | 9.40 ± 0.13 | 9.13 ± 0.12 | 9.56 ± 0.08
Reticulocytes (10^6^/μL) | 0.14 ± 0.01 | 0.15 ± 0.01 | 0.19 ± 0.01^**^ | 0.24 ± 0.02^**^
Mean cell volume (fL) | 43.9 ± 0.2 | 43.6 ± 0.3 | 44.0 ± 0.3 | 43.7 ± 0.3
Mean cell hemoglobin (pg) | 14.3 ± 0.1 | 14.1 ± 0.1 | 14.0 ± 0.1^*^ | 13.6 ± 0.1^**^
Mean cell hemoglobin concentration (g/dL) | 32.5 ± 0.1 | 32.3 ± 0.0^*^ | 31.9 ± 0.1^**^ | 31.1 ± 0.2^**^
Female
n | 10 | 9 | 9 | 12
Hematocrit (%) | 44.4 ± 0.7 | 44.5 ± 0.7 | 42.4 ± 0.8 | 41.4 ± 0.6^**^
Hemoglobin (g/dL) | 14.4 ± 0.2 | 14.5 ± 0.3 | 13.6 ± 0.3 | 13.0 ± 0.2^**^
Erythrocytes (10^6^/μL) | 10.11 ± 0.18 | 9.96 ± 0.20 | 9.50 ± 0.29^*^ | 9.12 ± 0.21^**^
Reticulocytes (10^6^/μL) | 0.14 ± 0.01 | 0.15 ± 0.02 | 0.17 ± 0.02 | 0.33 ± 0.04^**^
Mean cell volume (fL) | 44.0 ± 0.5 | 44.7 ± 0.5 | 44.8 ± 0.6 | 45.5 ± 0.5
Mean cell hemoglobin (pg) | 14.3 ± 0.2 | 14.6 ± 0.2 | 14.4 ± 0.2 | 14.2 ± 0.2
Mean cell hemoglobin concentration (g/dL) | 32.4 ± 0.2 | 32.6 ± 0.1 | 32.0 ± 0.1 | 31.3 ± 0.1^**^

* Significantly different (P≤0.05) from the vehicle control group by Dunn’s or Shirley’s test

** P≤0.01

a Mean ± standard error. Statistical tests were performed on unrounded data.

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the thyroid gland, kidney, pituitary gland, and mandibular lymph node. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables B1, B2, B3, and B4.

Thyroid Gland: Significantly increased treatment-related changes were observed in the thyroid glands of male and female mice (Tables 16, B2, and B4). Male and female groups had similar incidence rates with increased severities in females. The incidences of follicular cell hypertrophy and follicular secretory depletion were significantly increased in the 400 and 800 mg/L groups of males and females (Tables 16, B2, and B4). The incidences of lymphocyte cellular infiltrates were significantly increased in the 400 and 800 mg/L females.

Kidney: Absolute kidney weights were significantly decreased in 800 mg/L females when compared to controls (Table F3). Relative kidney weights were significantly increased in 400 and 800 mg/L males. The incidences of nephropathy were significantly increased in all exposed groups of males and in the 400 and 800 mg/L female groups (Tables 16, B2, and B4). These lesions were minimal to mild in severity. The incidences of renal tubule degeneration were significantly increased in 800 mg/L males and females (Tables 16, B2, and B4). Renal tubule degeneration consisted of tubule cell changes including vacuolization or flocculent cytoplasm in epithelial cells, necrosis of tubule epithelial cells, and faint basophilic cellular staining. The incidences of renal cell hypertrophy were significantly increased in 400 and 800 mg/L females. Renal tubule hypertrophy referred to tubules having palely stained enlarged epithelial cells that did not show other features suggesting degeneration.

Pituitary Gland: The incidence of pars distalis hypertrophy was significantly increased in 800 mg/L females (Tables 16 and B4). The hypertrophy was characterized by an increase in the size of chromophobes.

Lymph Node, Mandibular: The incidences of lymphoid hyperplasia were significantly increased in the 80 and 800 mg/L female groups (0 mg/L, 0/15; 80 mg/L, 4/15; 400 mg/L, 2/15; 800 mg/L, 5/15; Table B4). These lesions were characterized by increased numbers of lymphocytes and an increase in the size of the lymph nodes.

TABLE 16 Incidences of Selected Nonneoplastic Lesions in Tg.AC Hemizygous Mice in the 27-Week Drinking Water Study of Sodium Bromate

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Male
Thyroid Gland^a^ | 15 | 14 | 15 | 15
Follicular Cell, Hypertrophy^b^ | 1 (2.0)^c^ | 2 (1.5) | 12^**^ (1.6) | 15^**^ (2.0)
Follicular Depletion, Secretory | 4 (1.0) | 6 (1.0) | 15^**^ (1.1) | 15^**^ (1.3)
Kidney | 15 | 15 | 15 | 15
Nephropathy | 1 (1.0) | 7^*^ (1.0) | 10^**^ (1.0) | 14^**^ (1.6)
Renal Tubule, Degeneration | 0 | 0 | 0 | 10^**^ (1.3)
Female
Thyroid Gland | 15 | 13 | 13 | 15
Follicular Cell, Hypertrophy | 2 (1.0) | 2 (1.0) | 11^**^ (1.9) | 13^**^ (3.2)
Follicular Depletion, Secretory | 7 (1.1) | 7 (1.6) | 11^*^ (1.8) | 14^**^ (3.1)
Infiltration Cellular, Lymphocyte | 0 | 0 | 5^*^ (1.0) | 11^**^ (1.5)
Kidney | 15 | 15 | 15 | 15
Nephropathy | 2 (1.0) | 2 (1.0) | 10^**^ (1.0) | 13^**^ (1.8)
Renal Tubule, Degeneration | 0 | 0 | 2 (1.0) | 8^**^ (1.9)
Renal Tubule, Hypertrophy | 0 | 1 (1.0) | 5^*^ (1.0) | 12^**^ (1.8)
Pituitary Gland | 15 | 15 | 15 | 15
Pars Distalis, Hypertrophy | 0 | 0 | 0 | 6^**^ (2.2)

* Significantly different (P≤0.05) from the control group by the Fisher exact test

** P≤0.01

a Number of animals with tissue examined microscopically

b Number of animals with lesion

c Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

## 43-Week Drinking Water Study in Tg.AC Hemizygous Mice

### Survival

Estimates of 43-week survival probabilities for male and female mice are shown in Table 17. Although not statistically significant, survival was decreased in 400 mg/L females and 800 mg/L males and females compared to that of the control groups.

### Body Weights and Clinical Findings

Mean body weights of 400 and 800 mg/L male mice were less than those of the controls beginning at approximately weeks 35 and 3 of the study, respectively. Body weights of 80 and 800 mg/L females were less than those of the controls beginning at weeks 24 and 13 of the study, respectively (Tables 18 and 19; Figure 4). Water consumption by exposed mice was generally similar to that by controls throughout the study (Tables H3 and H4). Drinking water concentrations of 80, 400, and 800 mg/L resulted in average daily doses of approximately 11, 52, and 131 mg/kg to male mice and 15, 65, and 152 mg/kg to female mice. No clinical findings were attributed to sodium bromate administration.

TABLE 17 Survival of Tg.AC Hemizygous Mice in the 43-Week Drinking Water Study of Sodium Bromate

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Male
Animals initially in study | 10 | 10 | 10 | 10
Moribund | 2 | 2 | 4 | 3
Natural deaths | 2 | 1 | 0 | 3
Animals surviving to study termination | 6 | 7 | 6 | 4
Percent probability of survival at end of study^a^ | 60 | 70 | 60 | 40
Mean survival (days)^b^ | 251 | 244 | 263 | 260
Survival analysis^c^ | P=0.515 | P=1.000N | P=1.000N | P=0.826
Female
Animals initially in study | 10 | 10 | 10 | 10
Moribund | 3 | 4 | 4 | 7
Natural deaths | 0 | 1 | 2 | 1
Animals surviving to study termination | 7 | 5 | 4 | 2
Percent probability of survival at end of study | 70 | 50 | 40 | 20
Mean survival (days) | 246 | 249 | 238 | 194
Survival analysis | P=0.030 | P=0.740 | P=0.470 | P=0.089

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice).

c The result of the life table trend test (Tarone, 1975) is in the control column, and the results of the life table pairwise comparisons (Cox, 1972) with the controls are in the exposed group columns. A lower mortality in an exposure group is indicated by N.

TABLE 18 Mean Body Weights and Survival of Male Tg.AC Hemizygous Mice in the 43-Week Drinking Water Study of Sodium Bromate

Weeks on Study | 0 mg/L | | 80 mg/L | | | 400 mg/L | | | 800 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 23.3 | 10 | 23.6 | 101 | 10 | 23.6 | 101 | 10 | 23.6 | 101 | 10
2 | 24.4 | 10 | 24.3 | 100 | 10 | 24.8 | 102 | 10 | 23.2 | 95 | 10
3 | 25.9 | 10 | 25.0 | 97 | 10 | 26.1 | 101 | 10 | 24.1 | 93 | 10
4 | 28.2 | 10 | 28.0 | 99 | 10 | 28.4 | 101 | 10 | 25.8 | 92 | 10
5 | 29.0 | 10 | 29.3 | 101 | 10 | 29.3 | 101 | 10 | 27.4 | 95 | 10
6 | 29.4 | 10 | 30.2 | 103 | 10 | 30.6 | 104 | 10 | 28.7 | 98 | 10
7 | 30.9 | 10 | 31.7 | 103 | 10 | 30.8 | 100 | 10 | 29.4 | 95 | 10
8 | 32.1 | 10 | 32.4 | 101 | 10 | 31.8 | 99 | 10 | 29.7 | 93 | 10
9 | 32.5 | 10 | 33.1 | 102 | 10 | 32.1 | 99 | 10 | 30.6 | 94 | 10
10 | 33.4 | 10 | 34.2 | 102 | 10 | 32.6 | 98 | 10 | 30.5 | 91 | 10
11 | 33.3 | 10 | 33.9 | 102 | 10 | 32.8 | 99 | 10 | 30.1 | 90 | 10
12 | 34.3 | 10 | 35.0 | 102 | 10 | 33.2 | 97 | 10 | 30.3 | 88 | 10
13 | 35.1 | 10 | 36.0 | 103 | 10 | 33.9 | 97 | 10 | 30.7 | 88 | 10
14 | 35.6 | 10 | 36.5 | 103 | 9 | 34.2 | 96 | 10 | 30.4 | 85 | 10
15 | 36.2 | 9 | 37.5 | 104 | 8 | 34.9 | 96 | 10 | 30.4 | 84 | 10
16 | 34.8 | 9 | 36.7 | 106 | 8 | 33.9 | 97 | 10 | 30.2 | 87 | 10
17 | 36.2 | 9 | 37.1 | 103 | 8 | 34.3 | 95 | 10 | 31.4 | 87 | 10
18 | 36.8 | 9 | 37.7 | 102 | 8 | 34.8 | 95 | 10 | 31.6 | 86 | 10
19 | 36.7 | 9 | 36.3 | 99 | 8 | 34.5 | 94 | 10 | 32.1 | 88 | 9
20 | 36.8 | 9 | 37.6 | 102 | 8 | 35.8 | 97 | 10 | 32.6 | 89 | 9
21 | 37.1 | 9 | 37.2 | 100 | 8 | 36.0 | 97 | 10 | 32.2 | 87 | 9
22 | 38.1 | 9 | 37.2 | 98 | 8 | 36.0 | 95 | 9 | 32.1 | 84 | 9
23 | 37.8 | 9 | 36.7 | 97 | 8 | 36.5 | 97 | 9 | 31.4 | 83 | 9
24 | 37.8 | 9 | 36.6 | 97 | 8 | 35.6 | 94 | 9 | 31.4 | 83 | 9
25 | 37.7 | 9 | 36.5 | 97 | 8 | 35.8 | 95 | 9 | 31.6 | 84 | 9
26 | 38.7 | 9 | 37.5 | 97 | 8 | 36.2 | 94 | 9 | 32.2 | 83 | 9
27 | 38.3 | 9 | 37.4 | 98 | 8 | 35.8 | 94 | 9 | 32.3 | 84 | 9
28 | 39.6 | 8 | 37.2 | 94 | 8 | 38.8 | 98 | 8 | 33.0 | 83 | 9
29 | 39.2 | 8 | 40.2 | 103 | 7 | 37.5 | 96 | 8 | 32.7 | 83 | 9
30 | 38.4 | 8 | 39.5 | 103 | 7 | 37.2 | 97 | 8 | 32.9 | 86 | 9
31 | 38.0 | 8 | 40.2 | 106 | 7 | 37.6 | 99 | 8 | 32.5 | 86 | 9
32 | 37.9 | 8 | 39.9 | 105 | 7 | 37.8 | 100 | 8 | 33.1 | 87 | 8
33 | 39.3 | 7 | 40.9 | 104 | 7 | 38.1 | 97 | 8 | 33.6 | 86 | 8
34 | 39.1 | 7 | 40.8 | 104 | 7 | 37.0 | 95 | 8 | 33.6 | 86 | 8
35 | 42.7 | 6 | 41.2 | 97 | 7 | 37.7 | 88 | 8 | 32.3 | 76 | 8
36 | 42.6 | 6 | 41.9 | 98 | 7 | 37.7 | 89 | 8 | 32.5 | 76 | 8
37 | 42.5 | 6 | 41.7 | 98 | 7 | 39.6 | 93 | 7 | 32.3 | 76 | 7
38 | 42.6 | 6 | 41.0 | 96 | 7 | 39.3 | 92 | 7 | 30.6 | 72 | 7
39 | 43.2 | 6 | 42.7 | 99 | 7 | 38.6 | 89 | 7 | 30.1 | 70 | 6
40 | 43.8 | 6 | 42.0 | 96 | 7 | 39.1 | 89 | 7 | 29.0 | 66 | 6
41 | 43.0 | 6 | 42.2 | 98 | 7 | 40.7 | 95 | 6 | 29.0 | 67 | 5
42 | 42.1 | 6 | 42.1 | 100 | 7 | 40.6 | 96 | 6 | 29.9 | 71 | 4
Mean for weeks
1–13 | 30.1 | | 30.5 | 101 | | 30.0 | 100 | | 28.0 | 93
14–42 | 39.1 | | 39.0 | 100 | | 37.0 | 95 | | 31.7 | 82

TABLE 19 Mean Body Weights and Survival of Female Tg.AC Hemizygous Mice in the 43-Week Drinking Water Study of Sodium Bromate

Weeks on Study | 0 mg/L | | 80 mg/L | | | 400 mg/L | | | 800 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 19.2 | 10 | 19.5 | 102 | 10 | 19.2 | 100 | 10 | 19.2 | 100 | 10
2 | 19.6 | 10 | 19.3 | 99 | 10 | 19.7 | 101 | 10 | 19.3 | 99 | 10
3 | 20.3 | 10 | 20.6 | 102 | 10 | 20.4 | 101 | 10 | 21.7 | 107 | 9
4 | 23.0 | 10 | 22.0 | 96 | 10 | 22.9 | 100 | 10 | 22.7 | 99 | 9
5 | 23.9 | 10 | 23.7 | 99 | 10 | 23.8 | 100 | 10 | 23.4 | 98 | 9
6 | 25.1 | 10 | 24.6 | 98 | 10 | 24.6 | 98 | 10 | 24.1 | 96 | 9
7 | 24.6 | 10 | 25.1 | 102 | 9 | 24.8 | 101 | 10 | 24.4 | 99 | 9
8 | 26.2 | 10 | 25.8 | 99 | 9 | 25.7 | 98 | 10 | 24.9 | 95 | 9
9 | 25.0 | 10 | 26.2 | 105 | 9 | 25.7 | 103 | 10 | 25.2 | 101 | 9
10 | 25.6 | 9 | 26.3 | 103 | 9 | 26.0 | 102 | 10 | 25.1 | 98 | 9
11 | 25.3 | 9 | 26.3 | 104 | 9 | 25.2 | 100 | 10 | 24.6 | 97 | 9
12 | 25.8 | 9 | 26.6 | 103 | 9 | 26.2 | 102 | 10 | 24.6 | 95 | 9
13 | 25.8 | 9 | 27.1 | 105 | 9 | 27.1 | 105 | 10 | 24.1 | 93 | 9
14 | 26.1 | 9 | 27.4 | 105 | 9 | 27.0 | 103 | 10 | 24.0 | 92 | 9
15 | 27.6 | 8 | 28.5 | 103 | 9 | 27.4 | 99 | 10 | 25.2 | 91 | 8
16 | 28.5 | 8 | 27.4 | 96 | 9 | 26.8 | 94 | 10 | 24.6 | 86 | 8
17 | 28.8 | 8 | 28.1 | 98 | 9 | 28.2 | 98 | 10 | 24.9 | 87 | 8
18 | 28.9 | 8 | 29.2 | 101 | 9 | 29.0 | 100 | 9 | 27.0 | 93 | 7
19 | 30.4 | 8 | 29.6 | 97 | 9 | 30.0 | 99 | 9 | 26.4 | 87 | 7
20 | 29.5 | 8 | 29.7 | 101 | 9 | 30.1 | 102 | 9 | 26.4 | 90 | 7
21 | 30.2 | 8 | 30.1 | 100 | 9 | 29.8 | 99 | 9 | 26.4 | 87 | 7
22 | 30.5 | 8 | 29.7 | 97 | 8 | 28.3 | 93 | 8 | 26.5 | 87 | 7
23 | 29.8 | 8 | 29.9 | 100 | 8 | 28.6 | 96 | 8 | 25.9 | 87 | 7
24 | 32.1 | 8 | 29.5 | 92 | 8 | 29.9 | 93 | 8 | 25.2 | 79 | 7
25 | 31.8 | 8 | 29.7 | 93 | 8 | 30.3 | 95 | 8 | 25.9 | 81 | 7
26 | 32.1 | 8 | 29.5 | 92 | 8 | 31.7 | 99 | 7 | 26.0 | 81 | 7
27 | 33.8 | 8 | 29.2 | 86 | 8 | 32.1 | 95 | 7 | 26.6 | 79 | 7
28 | 34.0 | 8 | 30.3 | 89 | 8 | 32.8 | 97 | 7 | 27.1 | 80 | 6
29 | 34.2 | 8 | 29.9 | 87 | 8 | 33.3 | 97 | 7 | 26.4 | 77 | 6
30 | 33.4 | 8 | 30.0 | 90 | 8 | 34.2 | 102 | 6 | 27.2 | 81 | 4
31 | 33.4 | 8 | 29.7 | 89 | 8 | 34.4 | 103 | 6 | 27.8 | 83 | 4
32 | 33.6 | 8 | 29.8 | 89 | 8 | 33.6 | 100 | 6 | 28.3 | 84 | 4
33 | 34.6 | 8 | 29.5 | 85 | 8 | 34.8 | 101 | 6 | 28.3 | 82 | 4
34 | 35.3 | 8 | 28.9 | 82 | 8 | 35.2 | 100 | 6 | 27.4 | 78 | 4
35 | 34.9 | 8 | 28.3 | 81 | 8 | 34.8 | 100 | 6 | 28.8 | 83 | 4
36 | 34.8 | 7 | 29.7 | 85 | 8 | 35.6 | 102 | 6 | 28.3 | 81 | 4
37 | 35.3 | 7 | 29.1 | 82 | 8 | 36.2 | 103 | 6 | 28.5 | 81 | 4
38 | 35.1 | 7 | 29.4 | 84 | 7 | 35.6 | 101 | 6 | 28.7 | 82 | 4
39 | 34.8 | 7 | 29.5 | 85 | 7 | 35.1 | 101 | 6 | 26.9 | 77 | 4
40 | 34.7 | 7 | 29.8 | 86 | 7 | 35.1 | 101 | 6 | 24.0 | 69 | 3
41 | 33.9 | 7 | 29.2 | 86 | 7 | 33.9 | 100 | 6 | 23.6 | 70 | 2
42 | 33.6 | 7 | 29.4 | 88 | 5 | 37.8 | 113 | 4 | 23.1 | 69 | 2
Mean for weeks
1–13 | 23.8 | | 24.1 | 101 | | 23.9 | 101 | | 23.3 | 98
14–42 | 32.3 | | 29.3 | 91 | | 32.1 | 100 | | 26.4 | 82

FIGURE 4 Growth Curves for Male and Female Tg.AC Hemizygous Mice Exposed to Sodium Bromate in Drinking Water for 43 Weeks

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the thyroid gland, kidney, epididymis, testes, pituitary gland, thymus, and forestomach. Summaries of the incidences of neoplasms and nonneoplastic lesions are presented in Tables B5, B6, B7, and B8.

Thyroid Gland: Significant treatment-related changes were observed in thyroid glands of male and female mice (Tables 20, B6, and B8). The microscopic changes were similar to those observed at 27 weeks. The incidences of follicular cell hypertrophy were significantly increased in all exposed groups of males and females (Tables 20, B6, and B8). The severities increased with increasing exposure concentration in males and females. The incidences of follicular secretory depletion were increased significantly in all exposed groups of females, and severities increased with increasing exposure concentration. Incidences of lymphocyte cellular infiltrates increased with increasing exposure concentration in females (Tables 20 and B8). Significant increases in incidences occurred in 800 mg/L males and in 400 and 800 mg/L females.

TABLE 20 Incidences of Nonneoplastic Lesions of the Thyroid Gland in Tg.AC Hemizygous Mice in the 43-Week Drinking Water Study of Sodium Bromate

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Male
Number Examined Microscopically | 10 | 10 | 10 | 9
Follicular Cell, Hypertrophy^a^ | 0 | 6^**^ (1.0)^b^ | 8^**^ (2.0) | 8^**^ (3.5)
Infiltration Cellular, Lymphocyte | 0 | 0 | 0 | 4^*^ (1.8)
Female
Number Examined Microscopically | 10 | 9 | 10 | 10
Follicular Cell, Hypertrophy | 0 | 8^**^ (1.0) | 10^**^ (2.6) | 10^**^ (3.3)
Follicle, Depletion Secretory | 1 (2.0) | 8^**^ (1.3) | 9^**^ (3.0) | 10^**^ (3.3)
Infiltration Cellular, Lymphocyte | 0 | 2 (1.0) | 7^**^ (1.1) | 8^**^ (1.4)

* Significantly different (P≤0.05) from the control group by the Fisher exact test

** P≤0.01

a Number of animals with lesion

b Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

Kidney: The incidence of nephropathy was slightly increased in 800 mg/L males and 400 and 800 mg/L females (Tables 21, B6, and B8). The increases were not statistically significant. These lesions were minimal to moderate in severity. The incidences of renal tubule degeneration and renal cell hypertrophy were significantly increased in the 800 mg/L groups of males and females (Tables 21, B6, and B8).

Epididymis: Incidences of tubule degeneration were significantly increased in the 800 mg/L males (Tables 21 and B6). Epididymal tubules with degeneration had reduced numbers of spermatozoa and increased numbers of sloughed cells or had eosinophilic fluid completely devoid of cells.

Testes: Absolute testis weights were significantly decreased in 800 mg/L males when compared to controls (Table F4). Incidences of germinal epithelium degeneration increased with increasing exposure concentration. Significantly increased incidences occurred in the 800 mg/L groups (Tables 21 and B6). Microscopically, the degeneration was similar to that observed in the dermal study at 39 weeks. The incidence of interstitial cell hyperplasia was increased in the 800 mg/L group. The increase was not statistically significant.

Pituitary Gland: The incidence of pars distalis hypertrophy was significantly increased in 800 mg/L females and was characterized by an increase in the size of chromophobes (Tables 21 and B8).

Thymus: The incidence of atrophy was significantly increased in females exposed to 800 mg/L (0 mg/L, 2/10; 80 mg/L, 5/10; 400 mg/L, 6/10; 800 mg/L, 9/10; Table B8). The atrophy has an unknown relationship to sodium bromate exposure.

Forestomach: Combined incidences of multiple and single squamous cell papillomas of the forestomach were decreased in the 400 and 800 mg/L groups of male mice (4/10, 4/10, 1/10, 1/10; Table B7); the decreases were not significant. Combined incidences of multiple and single squamous cell papillomas of the forestomach were slightly increased in the 80 and 400 mg/L groups of female mice (1/10, 4/10, 3/10, 1/10; Table B5). The increases were not significant. The incidence of hyperkeratosis of the forestomach epithelium was significantly increased in 800 mg/L females (Tables 21 and B8). This increase was not accompanied by increases in epithelial hyperplasia or papillomas.

TABLE 21 Incidences of Selected Nonneoplastic Lesions in Tg.AC Hemizygous Mice in the 43-Week Drinking Water Study of Sodium Bromate

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Male
Kidney^a^ | 10 | 10 | 10 | 10
Nephropathy | 7 | 6 | 7 | 10
Renal Tubule, Degeneration^b^ | 0 | 0 | 1 (3.0)^c^ | 8^**^ (3.0)
Renal Tubule, Hypertrophy | 0 | 0 | 1 (1.0) | 6^**^ (1.3)
Epididymis | 10 | 10 | 10 | 10
Degeneration | 1 (4.0) | 1 (4.0) | 0 | 7^**^ (3.3)
Testes | 10 | 10 | 10 | 10
Germinal Epithelium, Degeneration | 0 | 0 | 3 (2.0) | 8^**^ (2.9)
Interstitial Cell, Hyperplasia | 0 | 0 | 0 | 3 (1.3)
Female
Kidney | 10 | 10 | 10 | 10
Nephropathy | 6 | 6 | 8 | 8
Renal Tubule, Degeneration | 0 | 0 | 0 | 7^**^ (2.3)
Renal Tubule, Hypertrophy | 0 | 0 | 2 (1.0) | 5^*^ (1.6)
Pituitary Gland | 10 | 10 | 9 | 10
Pars Distalis, Hypertrophy | 0 | 0 | 2 (1.0) | 6^**^ (2.2)
Forestomach | 10 | 10 | 10 | 10
Epithelium, Hyperkeratosis | 1 (2.0) | 2 (1.0) | 1 (1.0) | 7^**^ (1.3)

* Significantly different (P≤0.05) from the control group by the Fisher exact test

** P≤0.01

a Number of animals with tissue examined microscopically

b Number of animals with lesion

c Average severity grade of lesions in affected animals: 1=minimal, 2=mild, 3=moderate, 4=marked

## 27-Week Drinking Water Study in p53 Haploinsufficient Mice

### Survival

Estimates of 27-week survival probabilities for male and female mice are shown in Table 22. Survival of all exposed groups was similar to that of the control groups.

### Body Weights and Clinical Findings

Mean body weights of male mice were generally similar to those of the controls throughout the study. Mean body weights of 400 and 800 mg/L female mice were less than those of the control group after week 8 (Figure 5; Tables 23 and 24). Water consumption by exposed mice was generally similar to that by controls throughout the study (Tables H5 and H6). Drinking water concentrations of 80, 400, and 800 mg/L resulted in average daily doses of approximately 8, 39, and 74 mg/kg to male mice and 13, 72, and 136 mg/kg to female mice. There were no clinical findings attributed to sodium bromate administration.

TABLE 22 Survival of p53 Haploinsufficient Mice in the 27-Week Drinking Water Study of Sodium Bromate

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Male
Animals initially in study | 15 | 15 | 15 | 15
Moribund | 0 | 1 | 1 | 0
Natural deaths | 1 | 0 | 0 | 1
Animals surviving to study termination | 14 | 14 | 14 | 14
Percent probability of survival at end of study^a^ | 93 | 93 | 93 | 93
Mean survival (days)^b^ | 183 | 181 | 180 | 179
Survival analysis^c^ | P=1.000 | P=1.000 | P=1.000 | P=1.000
Female
Animals initially in study | 15 | 15 | 15 | 15
Natural deaths | 1 | 0 | 0 | 1
Animals surviving to study termination | 14 | 15 | 15 | 14
Percent probability of survival at end of study | 93 | 100 | 100 | 93
Mean survival (days) | 183 | 185 | 185 | 181
Survival analysis | P=1.000 | P=1.000N | P=1.000N | P=1.000

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice).

c The result of the life table trend test (Tarone, 1975) is in the control column, and the results of the life table pairwise comparisons (Cox, 1972) with the controls are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

FIGURE 5 Growth Curves for Male and Female p53 Haploinsufficient Mice Exposed to Sodium Bromate in Drinking Water for 27 Weeks

TABLE 23 Mean Body Weights and Survival of Male p53 Haploinsufficient Mice in the 27-Week Drinking Water Study of Sodium Bromate

Weeks on Study | 0 mg/L | | 80 mg/L | | | 400 mg/L | | | 800 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 24.2 | 15 | 24.8 | 103 | 15 | 24.8 | 103 | 15 | 24.6 | 102 | 15
2 | 25.0 | 15 | 25.7 | 103 | 15 | 25.6 | 102 | 15 | 24.6 | 98 | 15
3 | 26.2 | 15 | 26.8 | 102 | 15 | 27.0 | 103 | 15 | 25.9 | 99 | 15
4 | 27.2 | 15 | 27.7 | 102 | 15 | 28.0 | 103 | 15 | 26.5 | 97 | 15
5 | 28.4 | 15 | 29.3 | 103 | 15 | 29.5 | 104 | 15 | 28.2 | 99 | 15
6 | 29.7 | 15 | 30.9 | 104 | 15 | 31.1 | 105 | 15 | 29.6 | 100 | 15
7 | 31.3 | 15 | 32.8 | 105 | 15 | 32.7 | 105 | 15 | 30.9 | 99 | 15
8 | 32.2 | 15 | 33.8 | 105 | 15 | 34.2 | 106 | 15 | 31.8 | 99 | 15
9 | 33.5 | 15 | 34.9 | 104 | 15 | 35.4 | 106 | 15 | 33.3 | 99 | 15
10 | 35.1 | 15 | 36.4 | 104 | 15 | 36.7 | 105 | 15 | 34.5 | 98 | 15
11 | 36.4 | 15 | 37.7 | 104 | 15 | 37.9 | 104 | 15 | 35.5 | 98 | 15
12 | 37.7 | 15 | 38.9 | 103 | 15 | 39.1 | 104 | 15 | 36.4 | 97 | 15
13 | 38.7 | 15 | 40.0 | 103 | 15 | 39.9 | 103 | 15 | 37.4 | 97 | 15
14 | 39.9 | 15 | 40.9 | 103 | 15 | 40.1 | 101 | 15 | 38.0 | 95 | 15
15 | 41.2 | 15 | 42.2 | 102 | 15 | 41.3 | 100 | 15 | 38.8 | 94 | 15
16 | 41.6 | 15 | 43.0 | 103 | 15 | 41.6 | 100 | 15 | 39.0 | 94 | 15
17 | 42.2 | 15 | 43.3 | 103 | 15 | 42.2 | 100 | 15 | 40.7 | 96 | 14
18 | 43.1 | 15 | 44.9 | 104 | 15 | 42.9 | 100 | 15 | 41.5 | 96 | 14
19 | 43.6 | 15 | 44.9 | 103 | 15 | 43.3 | 99 | 15 | 42.0 | 96 | 14
20 | 44.0 | 15 | 45.1 | 103 | 15 | 45.4 | 103 | 14 | 42.6 | 97 | 14
21 | 44.4 | 15 | 45.7 | 103 | 15 | 45.8 | 103 | 14 | 42.8 | 96 | 14
22 | 44.5 | 15 | 46.6 | 105 | 14 | 46.1 | 104 | 14 | 43.7 | 98 | 14
23 | 45.3 | 15 | 47.4 | 105 | 14 | 46.4 | 102 | 14 | 44.4 | 98 | 14
24 | 45.6 | 15 | 47.6 | 104 | 14 | 46.8 | 103 | 14 | 45.1 | 99 | 14
25 | 46.3 | 15 | 48.0 | 104 | 14 | 47.4 | 102 | 14 | 45.7 | 99 | 14
26 | 46.5 | 14 | 48.1 | 103 | 14 | 47.2 | 102 | 14 | 45.5 | 98 | 14
Mean for weeks
1–13 | 31.2 | | 32.3 | 103 | | 32.5 | 104 | | 30.7 | 98
14–26 | 43.7 | | 45.2 | 103 | | 44.3 | 101 | | 42.3 | 97

TABLE 24 Mean Body Weights and Survival of Female p53 Haploinsufficient Mice in the 27-Week Drinking Water Study of Sodium Bromate

Weeks on Study | 0 mg/L | | 80 mg/L | | | 400 mg/L | | | 800 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 20.1 | 15 | 19.9 | 99 | 15 | 19.6 | 98 | 15 | 19.9 | 99 | 15
2 | 20.8 | 15 | 20.5 | 99 | 15 | 20.3 | 98 | 15 | 20.4 | 98 | 15
3 | 21.4 | 15 | 21.2 | 99 | 15 | 21.1 | 99 | 15 | 21.0 | 98 | 15
4 | 22.3 | 15 | 21.9 | 98 | 15 | 21.3 | 96 | 15 | 21.6 | 97 | 15
5 | 22.6 | 15 | 22.3 | 99 | 15 | 21.7 | 96 | 15 | 22.1 | 98 | 15
6 | 23.0 | 15 | 22.8 | 99 | 15 | 22.2 | 97 | 15 | 22.4 | 97 | 15
7 | 23.8 | 15 | 23.4 | 98 | 15 | 22.7 | 95 | 15 | 23.1 | 97 | 15
8 | 24.2 | 15 | 23.8 | 98 | 15 | 22.9 | 95 | 15 | 23.1 | 96 | 15
9 | 24.9 | 15 | 24.4 | 98 | 15 | 23.5 | 94 | 15 | 23.4 | 94 | 15
10 | 25.6 | 15 | 25.2 | 98 | 15 | 24.2 | 95 | 15 | 24.0 | 94 | 15
11 | 26.2 | 15 | 25.5 | 97 | 15 | 24.3 | 93 | 15 | 24.0 | 92 | 15
12 | 26.2 | 15 | 26.0 | 99 | 15 | 24.8 | 95 | 15 | 24.2 | 92 | 15
13 | 27.4 | 15 | 26.9 | 98 | 15 | 24.8 | 91 | 15 | 24.6 | 90 | 15
14 | 28.0 | 15 | 27.1 | 97 | 15 | 25.9 | 93 | 15 | 25.1 | 90 | 15
15 | 28.4 | 15 | 27.6 | 97 | 15 | 26.4 | 93 | 15 | 25.5 | 90 | 15
16 | 29.3 | 15 | 28.4 | 97 | 15 | 26.9 | 92 | 15 | 26.1 | 89 | 15
17 | 30.4 | 15 | 29.2 | 96 | 15 | 27.5 | 91 | 15 | 26.8 | 88 | 15
18 | 30.2 | 15 | 28.9 | 96 | 15 | 27.7 | 92 | 15 | 27.0 | 89 | 15
19 | 30.5 | 15 | 28.8 | 94 | 15 | 28.0 | 92 | 15 | 27.0 | 89 | 14
20 | 30.8 | 15 | 29.7 | 96 | 15 | 28.5 | 93 | 15 | 27.2 | 88 | 14
21 | 31.3 | 15 | 30.3 | 97 | 15 | 29.0 | 93 | 15 | 27.5 | 88 | 14
22 | 31.3 | 15 | 31.0 | 99 | 15 | 30.1 | 96 | 15 | 28.4 | 91 | 14
23 | 32.4 | 14 | 31.9 | 99 | 15 | 31.1 | 96 | 15 | 29.6 | 91 | 14
24 | 32.8 | 14 | 33.0 | 101 | 15 | 31.8 | 97 | 15 | 29.3 | 89 | 14
25 | 33.6 | 14 | 33.8 | 101 | 15 | 32.6 | 97 | 15 | 29.9 | 89 | 14
26 | 34.3 | 14 | 33.7 | 98 | 15 | 33.2 | 97 | 15 | 30.3 | 88 | 14
Mean for weeks
1–13 | 23.7 | | 23.4 | 99 | | 22.6 | 95 | | 22.6 | 95
14–26 | 31.0 | | 30.3 | 98 | | 29.1 | 94 | | 27.7 | 89

### Hematology

In contrast to the results of the studies conducted in Tg.AC hemizygous mice, the erythron in p53 haploinsufficient mice demonstrated minimal (less than or equal to 5%) increases in erythrocyte counts in 400 mg/L female and 800 mg/L male and female mice (Tables 25 and E3). Similar to the observations with Tg.AC mice, minimal (4% or less) decreases in mean cell hemoglobin were observed in 800 mg/L male and female p53 haploinsufficient mice and a slight (37%) increase in reticulocyte counts was observed in 800 mg/L males. The biological significance of these erythron changes was unknown but indicates that the two mouse strains responded differently when administered the same concentrations of sodium bromate in drinking water.

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions. There were no neoplasms or nonneoplastic lesions in either male or female p53 haploinsufficient mice that were attributed to exposure to sodium bromate (Tables C1, C2, C3 and C4).

TABLE 25 Selected Hematology Data for p53 Haploinsufficient Mice in the 27-Week Drinking Water Study of Sodium Bromate^a^

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Male
n | 14 | 14 | 13 | 14
Hematocrit (%) | 46.7 ± 0.4 | 47.5 ± 0.2 | 46.4 ± 0.6 | 47.5 ± 0.7
Hemoglobin (g/dL) | 15.2 ± 0.1 | 15.4 ± 0.1 | 14.9 ± 0.2 | 15.2 ± 0.2
Erythrocytes (10^6^/μL) | 10.41 ± 0.13 | 10.52 ± 0.08 | 10.33 ± 0.12 | 10.87 ± 0.19^*^
Reticulocytes (10^6^/μL) | 0.15 ± 0.01 | 0.16 ± 0.01 | 0.17 ± 0.02 | 0.20 ± 0.01^*^
Mean cell volume (fL) | 44.9 ± 0.3 | 45.2 ± 0.2 | 44.9 ± 0.2 | 43.8 ± 0.3
Mean cell hemoglobin (pg) | 14.6 ± 0.1 | 14.6 ± 0.1 | 14.4 ± 0.1 | 14.0 ± 0.1^**^
Mean cell hemoglobin concentration (g/dL) | 32.5 ± 0.1 | 32.5 ± 0.1 | 32.1 ± 0.1 | 32.0 ± 0.1^**^
Female
n | 14 | 15 | 15 | 14
Hematocrit (%) | 46.1 ± 0.4 | 47.2 ± 0.4 | 48.0 ± 0.6^*^ | 47.0 ± 0.4
Hemoglobin (g/dL) | 14.8 ± 0.1 | 15.2 ± 0.1 | 15.3 ± 0.2^*^ | 15.0 ± 0.2
Erythrocytes (10^6^/μL) | 10.25 ± 0.09 | 10.49 ± 0.08 | 10.76 ± 0.13^**^ | 10.72 ± 0.09^**^
Reticulocytes (10^6^/μL) | 0.20 ± 0.01 | 0.18 ± 0.01 | 0.17 ± 0.01 | 0.20 ± 0.01
Mean cell volume (fL) | 45.0 ± 0.2 | 44.9 ± 0.1 | 44.7 ± 0.2 | 43.9 ± 0.2^**^
Mean cell hemoglobin (pg) | 14.4 ± 0.1 | 14.5 ± 0.1 | 14.3 ± 0.0 | 14.0 ± 0.1^**^
Mean cell hemoglobin concentration (g/dL) | 32.0 ± 0.1 | 32.3 ± 0.1 | 32.0 ± 0.1 | 31.8 ± 0.1

* Significantly different (P≤0.05) from the vehicle control group by Dunn’s or Shirley’s test

** P≤0.01

a Mean ± standard error. Statistical tests were performed on unrounded data.

## 43-Week Drinking Water Study

### Survival

Estimates of 43-week survival probabilities for male and female mice are shown in Table 26. Survival of all exposed groups was similar to that of the control groups.

### Body Weights and Clinical Findings

Mean body weights of male mice were generally similar to those of the controls throughout the study. Mean body weights of 400 and 800 mg/L females were less than those of the controls beginning at weeks 11 and 16 of the study, respectively (Tables 27 and 28; Figure 6). Water consumption by exposed mice was generally similar to that by controls throughout the study (Tables H7 and H8). Drinking water concentrations of 80, 400, and 800 mg/L resulted in average daily doses of approximately 7, 37, and 65 mg/kg to male mice and 11, 58, and 107 mg/kg to female mice. There were no clinical findings attributed to the administration of sodium bromate.

TABLE 26 Survival of p53 Haploinsufficient Mice in the 43-Week Drinking Water Study of Sodium Bromate

| 0 mg/L | 80 mg/L | 400 mg/L | 800 mg/L
Male
Animals initially in study | 10 | 10 | 10 | 10
Moribund | 1 | 2 | 0 | 0
Natural deaths | 0 | 0 | 2 | 1
Animals surviving to study termination | 9 | 8 | 8 | 9
Percent probability of survival at end of study^a^ | 90 | 80 | 80 | 90
Mean survival (days)^b^ | 293 | 284 | 289 | 288
Survival analysis^c^ | P=1.000N | P=0.924 | P=0.976 | P=1.000
Female
Animals initially in study | 10 | 10 | 10 | 10
Moribund | 0 | 1 | 0 | 0
Natural death | 1 | 0 | 0 | 0
Animals surviving to study termination | 9 | 9 | 10 | 10
Percent probability of survival at end of study | 90 | 90 | 100 | 100
Mean survival (days) | 294 | 293 | 295 | 295
Survival analysis | P=0.412N | P=1.000 | P=1.000N | P=1.000N

a Kaplan-Meier determinations

b Mean of all deaths (uncensored, censored, and terminal sacrifice).

c The result of the life table trend test (Tarone, 1975) is in the control column, and the results of the life table pairwise comparisons (Cox, 1972) with the controls are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

TABLE 27 Mean Body Weights and Survival of Male p53 Haploinsufficient Mice in the 43-Week Drinking Water Study of Sodium Bromate

Weeks on Study | 0 mg/L | | 80 mg/L | | | 400 mg/L | | | 800 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 24.8 | 10 | 24.6 | 99 | 10 | 25.2 | 102 | 10 | 24.7 | 100 | 10
2 | 25.6 | 10 | 25.4 | 99 | 10 | 25.9 | 101 | 10 | 24.5 | 96 | 10
3 | 27.2 | 10 | 26.8 | 99 | 10 | 27.3 | 100 | 10 | 26.2 | 96 | 10
4 | 28.1 | 10 | 27.5 | 98 | 10 | 28.4 | 101 | 10 | 27.3 | 97 | 10
5 | 29.2 | 10 | 28.7 | 98 | 10 | 29.5 | 101 | 10 | 28.5 | 98 | 10
6 | 30.8 | 10 | 29.8 | 97 | 10 | 30.7 | 100 | 10 | 29.8 | 97 | 10
7 | 32.7 | 10 | 31.8 | 97 | 10 | 32.7 | 100 | 10 | 31.8 | 97 | 10
8 | 33.7 | 10 | 33.0 | 98 | 10 | 33.9 | 101 | 10 | 32.8 | 97 | 10
9 | 34.7 | 10 | 33.8 | 97 | 10 | 33.3 | 96 | 10 | 33.6 | 97 | 10
10 | 35.9 | 10 | 35.3 | 98 | 10 | 35.0 | 98 | 10 | 34.6 | 96 | 10
11 | 37.2 | 10 | 36.7 | 99 | 10 | 36.7 | 99 | 10 | 35.2 | 95 | 10
12 | 38.6 | 10 | 36.7 | 95 | 10 | 37.5 | 97 | 10 | 36.2 | 94 | 10
13 | 39.9 | 10 | 38.6 | 97 | 10 | 39.0 | 98 | 10 | 37.3 | 94 | 10
14 | 40.6 | 10 | 40.0 | 99 | 10 | 40.0 | 99 | 10 | 38.3 | 94 | 10
15 | 42.0 | 10 | 41.1 | 98 | 10 | 41.0 | 98 | 10 | 39.5 | 94 | 10
16 | 42.5 | 10 | 42.0 | 99 | 10 | 41.7 | 98 | 10 | 40.0 | 94 | 10
17 | 43.6 | 10 | 42.8 | 98 | 10 | 42.4 | 97 | 10 | 40.5 | 93 | 10
18 | 44.3 | 10 | 44.0 | 99 | 10 | 43.0 | 97 | 10 | 41.3 | 93 | 10
19 | 45.3 | 10 | 44.8 | 99 | 10 | 43.9 | 97 | 10 | 42.2 | 93 | 10
20 | 45.8 | 10 | 45.1 | 99 | 10 | 44.3 | 97 | 10 | 43.0 | 94 | 10
21 | 46.3 | 10 | 45.8 | 99 | 10 | 44.9 | 97 | 10 | 43.7 | 94 | 10
22 | 46.7 | 10 | 46.3 | 99 | 10 | 45.3 | 97 | 10 | 44.1 | 94 | 10
23 | 46.8 | 10 | 45.9 | 98 | 10 | 46.0 | 98 | 10 | 44.8 | 96 | 10
25 | 47.5 | 10 | 47.7 | 100 | 10 | 47.3 | 100 | 10 | 46.4 | 98 | 10
26 | 48.4 | 10 | 47.3 | 98 | 10 | 48.0 | 99 | 10 | 47.2 | 98 | 10
27 | 48.1 | 10 | 48.1 | 100 | 10 | 47.8 | 99 | 10 | 46.7 | 97 | 10
28 | 49.5 | 10 | 49.3 | 100 | 10 | 48.9 | 99 | 10 | 47.6 | 96 | 10
29 | 49.3 | 10 | 49.0 | 99 | 10 | 48.9 | 99 | 10 | 47.9 | 97 | 10
30 | 49.5 | 10 | 48.4 | 98 | 10 | 49.0 | 99 | 10 | 48.2 | 97 | 10
31 | 49.8 | 10 | 47.7 | 96 | 10 | 49.5 | 99 | 10 | 48.7 | 98 | 10
32 | 50.1 | 10 | 49.8 | 99 | 9 | 48.8 | 97 | 10 | 47.2 | 94 | 10
33 | 50.4 | 10 | 50.2 | 100 | 9 | 49.6 | 98 | 10 | 48.6 | 96 | 9
34 | 50.1 | 10 | 50.5 | 101 | 9 | 48.9 | 98 | 10 | 48.5 | 97 | 9
35 | 49.2 | 10 | 50.4 | 102 | 9 | 49.5 | 101 | 10 | 48.9 | 99 | 9
36 | 49.6 | 10 | 50.8 | 102 | 9 | 50.1 | 101 | 9 | 49.5 | 100 | 9
37 | 50.4 | 10 | 50.6 | 100 | 9 | 50.3 | 100 | 9 | 50.2 | 100 | 9
38 | 50.2 | 10 | 51.3 | 102 | 8 | 50.8 | 101 | 9 | 50.5 | 101 | 9
39 | 50.2 | 10 | 51.4 | 102 | 8 | 51.0 | 102 | 9 | 50.5 | 101 | 9
40 | 50.0 | 10 | 52.1 | 104 | 8 | 51.5 | 103 | 9 | 51.2 | 102 | 9
41 | 51.8 | 9 | 52.6 | 102 | 8 | 50.8 | 98 | 9 | 51.7 | 100 | 9
42 | 51.4 | 9 | 52.5 | 102 | 8 | 50.9 | 99 | 8 | 51.2 | 100 | 9
Mean for weeks
1–13 | 32.2 | | 31.4 | 98 | | 31.9 | 99 | | 31.0 | 96
14–42 | 47.8 | | 47.8 | 100 | | 47.3 | 99 | | 46.4 | 97

TABLE 28 Mean Body Weights and Survival of Female p53 Haploinsufficient Mice in the 43-Week Drinking Water Study of Sodium Bromate

Weeks on Study | 0 mg/L | | 80 mg/L | | | 400 mg/L | | | 800 mg/L
Weeks on Study | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of controls) | No. of Survivors
1 | 19.6 | 10 | 20.0 | 102 | 10 | 19.7 | 101 | 10 | 19.8 | 101 | 10
2 | 20.5 | 10 | 20.4 | 100 | 10 | 20.0 | 98 | 10 | 19.8 | 97 | 10
3 | 21.2 | 10 | 21.6 | 102 | 10 | 20.7 | 98 | 10 | 21.1 | 100 | 10
4 | 21.9 | 10 | 22.2 | 101 | 10 | 21.6 | 99 | 10 | 21.4 | 98 | 10
5 | 22.1 | 10 | 23.0 | 104 | 10 | 22.0 | 100 | 10 | 22.3 | 101 | 10
6 | 22.5 | 10 | 23.4 | 104 | 10 | 22.0 | 98 | 10 | 22.2 | 99 | 10
7 | 23.1 | 10 | 23.9 | 104 | 10 | 22.4 | 97 | 10 | 23.0 | 100 | 10
8 | 23.6 | 10 | 24.0 | 102 | 10 | 22.5 | 95 | 10 | 23.2 | 98 | 10
9 | 23.4 | 10 | 24.4 | 104 | 10 | 22.7 | 97 | 10 | 23.4 | 100 | 10
10 | 24.2 | 10 | 24.6 | 102 | 10 | 23.3 | 96 | 10 | 23.9 | 99 | 10
11 | 24.9 | 10 | 25.3 | 102 | 10 | 23.4 | 94 | 10 | 24.5 | 98 | 10
12 | 25.7 | 10 | 25.9 | 101 | 10 | 23.8 | 93 | 10 | 24.7 | 96 | 10
13 | 26.4 | 10 | 27.0 | 102 | 10 | 24.7 | 94 | 10 | 25.4 | 96 | 10
14 | 27.0 | 10 | 27.3 | 101 | 10 | 24.4 | 90 | 10 | 25.6 | 95 | 10
15 | 27.6 | 10 | 27.7 | 100 | 10 | 24.6 | 89 | 10 | 26.1 | 95 | 10
16 | 28.8 | 10 | 28.5 | 99 | 10 | 25.3 | 88 | 10 | 26.9 | 93 | 10
17 | 29.7 | 10 | 29.3 | 99 | 10 | 25.7 | 87 | 10 | 27.3 | 92 | 10
18 | 30.5 | 10 | 30.4 | 100 | 10 | 26.5 | 87 | 10 | 28.3 | 93 | 10
19 | 31.1 | 10 | 31.5 | 101 | 10 | 27.1 | 87 | 10 | 28.7 | 92 | 10
20 | 31.7 | 10 | 32.5 | 103 | 10 | 27.5 | 87 | 10 | 28.6 | 90 | 10
21 | 32.5 | 10 | 33.0 | 102 | 10 | 28.5 | 88 | 10 | 29.3 | 90 | 10
22 | 33.2 | 10 | 33.4 | 101 | 10 | 28.3 | 85 | 10 | 29.9 | 90 | 10
23 | 33.8 | 10 | 33.3 | 99 | 10 | 29.3 | 87 | 10 | 30.9 | 91 | 10
25 | 35.9 | 10 | 35.3 | 98 | 10 | 30.3 | 84 | 10 | 32.0 | 89 | 10
26 | 36.6 | 10 | 35.4 | 97 | 10 | 31.5 | 86 | 10 | 33.1 | 90 | 10
27 | 37.1 | 10 | 37.0 | 100 | 10 | 31.9 | 86 | 10 | 33.6 | 91 | 10
28 | 38.9 | 10 | 38.6 | 99 | 10 | 33.4 | 86 | 10 | 35.0 | 90 | 10
29 | 38.5 | 10 | 38.8 | 101 | 10 | 33.5 | 87 | 10 | 35.3 | 92 | 10
30 | 39.0 | 10 | 39.5 | 101 | 10 | 33.1 | 85 | 10 | 36.1 | 93 | 10
31 | 39.8 | 10 | 40.2 | 101 | 10 | 33.5 | 84 | 10 | 36.8 | 93 | 10
32 | 40.7 | 10 | 40.5 | 100 | 10 | 34.9 | 86 | 10 | 37.0 | 91 | 10
33 | 41.3 | 10 | 41.1 | 100 | 10 | 35.3 | 86 | 10 | 36.2 | 88 | 10
34 | 42.2 | 10 | 42.2 | 100 | 10 | 35.0 | 83 | 10 | 37.6 | 89 | 10
35 | 42.4 | 10 | 42.7 | 101 | 10 | 35.9 | 85 | 10 | 38.0 | 90 | 10
36 | 43.4 | 10 | 43.5 | 100 | 10 | 36.8 | 85 | 10 | 39.0 | 90 | 10
37 | 44.5 | 10 | 44.5 | 100 | 10 | 37.9 | 85 | 10 | 39.5 | 89 | 10
38 | 45.2 | 10 | 44.0 | 97 | 10 | 37.6 | 83 | 10 | 40.5 | 90 | 10
39 | 44.6 | 10 | 44.3 | 99 | 10 | 37.9 | 85 | 10 | 40.8 | 92 | 10
40 | 44.1 | 10 | 44.4 | 101 | 10 | 38.9 | 88 | 10 | 41.5 | 94 | 10
41 | 45.0 | 10 | 46.1 | 102 | 9 | 38.9 | 86 | 10 | 42.2 | 94 | 10
42 | 47.4 | 9 | 46.1 | 97 | 9 | 38.6 | 81 | 10 | 42.1 | 89 | 10
Mean for weeks
1–13 | 23.0 | | 23.5 | 102 | | 22.2 | 97 | | 22.7 | 99
14–42 | 37.6 | | 37.5 | 100 | | 32.2 | 86 | | 34.2 | 91

FIGURE 6 Growth Curves for Male and Female p53 Haploinsufficient Mice Exposed to Sodium Bromate in Drinking Water for 43 Weeks

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions. No treatment-related changes in the incidences of neoplasms or nonneoplastic lesions were observed in either male or female p53 haploinsufficient mice (Tables C5, C6, C7, and C8).

## Genetic Toxicology

Three independent tests for micronucleus induction by sodium bromate were conducted using two strains of transgenic mice. In each test, male and female mice were treated for a period of 26 (dermal) or 27 (drinking water) weeks; at the end of the treatment period, peripheral blood normochromatic (mature) erythrocytes were analyzed for frequency of micronucleated cells. Tg.AC hemizygous mice were dosed by dermal application (Table D1) or exposed via drinking water (Table D2); p53 haploinsufficient mice were exposed through drinking water (Table D3). Results of all three tests were positive in both male and female mice, and were based both on a significant trend as well as significant pairwise comparisons between individual treatment groups and the concurrent control. From the data, it appears that the Tg.AC hemizygous mice were more responsive than the p53 haploinsufficient mice to induction of micronuclei by sodium bromate, particularly if the same route (drinking water) is compared. Significant increases in the percentage of polychromatic erythrocytes among total erythrocytes were observed in male and female Tg.AC hemizygous mice exposed via drinking water and in male Tg.AC hemizygous mice dosed dermally with sodium bromate. No significant alterations in the percentage of polychromatic erythrocytes were seen in female Tg.AC hemizygous mice treated by the dermal route or in male or female p53 haploinsufficient mice.