# INTRODUCTION

SODIUM BROMATE

CAS No. 7789-38-0

Chemical Formula: NaBrO_3_ Molecular Weight: 150.9

Synonyms: Bromic acid, sodium salt

Trade names: Dyetone, Neutralizer K-126, Neutralizer K-140, Neutralizer K-938

## Chemical and Physical Properties

Sodium bromate is an ionic solid that appears as white granules or a crystalline powder, has no odor or taste, has a melting point of 381° C and a density of 3.4 g/mL, and is soluble in water and insoluble in organic vehicles such as 95% ethanol and acetone (Merck, 1983; HSDB, 2003). In the absence of information on sodium bromate, information on potassium bromate will be presented, as both salts produce similar effects and are roughly equivalent in the delivery of bromate ions.

## Production, Use, and Human Exposure

Sodium bromate is produced by passing bromine through a solution of sodium carbonate (HSDB, 2003).

Sodium bromate is used as an analytical reagent, in the oxidation of sulfur and vat dyes, and for cleaning boilers. As a mixture with sodium bromide, it is used for dissolving gold from its ores (HSDB, 2003). The cosmetic industry uses sodium bromate and potassium bromate as neutralizers or oxidizers in hair wave preparations. In 1991, the cosmetic industry voluntarily reported to the Food and Drug Administration (FDA) that sodium bromate was present in 61 cosmetic formulations, with concentrations ranging from 10% to 25%; there is no FDA requirement to report this information (Fed. Regist., 1992; CIREP, 1994). No information regarding the estimated amount of sodium bromate produced, imported, or exported for the United States or worldwide was found in the literature.

Sodium bromate and potassium bromate are by-products of the water disinfection process. Bromate is one of the disinfection by-products formed during the ozonation of source water containing bromide. Bromide is naturally present in water and the ozonation of waters containing the bromide ion (Br^−^) results in the oxidation of Br^−^ to hypobromous acid (HOBr) and further oxidation of the hypobromite ion (BrO^−^) to bromate (BrO3^−^) (Haag and Holgné, 1983; Glaze, 1986). No information was found reporting the concentrations of bromate in ozonated waters, but laboratory studies indicate that the rate and extent of bromate formation depends on ozone concentration, pH, and contact time (Haag and Holgné, 1983).

Pilot laboratory studies indicated that 60 or 70 µg/L bromate could be observed following treatment of raw water containing 1 or 2 mg/L bromide, respectively, with 2 mg/L ozone (McGuire et al., 1990). The addition of chlorine to water also results in oxidation of bromide to hypobromous acid (Rook, 1974). Once hypobromous acid has been formed, it is possible for bromate to be formed through disproportionation. However, during chlorination, the organic substances in raw water react with the hypobromite ion to produce brominated organic disinfection by-products reducing the concentration of hypobromite that is able to disproportionate to bromate (Bull and Kopfler, 1991). The maximum contaminant level established by the United States Environmental Protection Agency for bromate is 10 µg/L (40 CFR §141.64).

In the workplace, the American Industrial Hygiene Association (1981) requires the use of a dust respirator for airborne concentrations of sodium or potassium bromate in excess of 100 mg/m^3^. For the public, the Consumer Product Safety Commission requires that all home permanent wave neutralizing solutions containing greater than 600 mg sodium bromate or 50 mg potassium bromate be enclosed in child-resistant packages (16 CFR §1700.14).

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

Bromate appears to be rapidly absorbed from the gastrointestinal tract, at least in part unchanged, following oral administration. Fujii et al. (1984) administered a single dose of potassium bromate (50 mg/kg) intragastrically to male Wistar rats. Approximately 35% and 26% of the dose was excreted in the urine as bromate and bromide, respectively, 24 hours after the treatment. The feces contained approximately 1% of the dose. Bromate was not detected in the blood or other tissues after 24 hours. However, bromide was significantly increased in the kidney, pancreas, stomach, small intestine, red blood cells, and plasma, indicating that bromate is distributed to several body tissues and reduced to bromide. The disappearance of potassium bromate from the gastrointestinal tract and plasma and its excretion in urine was investigated by administering 100 mg/kg orally to rats (Fujii et al., 1984). Bromate disappeared gradually from the stomach. Maximum concentrations of bromate were observed in the small intestine after 30 minutes and levels were undetectable after 4 hours. Peak plasma and urine concentrations were observed 15 minutes and 1 hour after dosing, respectively. Plasma and urine levels decreased rapidly and were undetectable after 2 and 4 hours, respectively. To determine the dose-response relationship of the excretion of bromate and bromide, a solution of potassium bromate was administered orally to rats at 0, 0.625, 1.25, 2.5, 5.0, 10.0, 20.0, 40.0, 60.0, 80.0, or 100 mg/kg (Fujii et al., 1984). No bromate was detected in the urine of rats administered up to 2.5 mg/kg. However at doses higher than 5 mg/kg, dose-related increases in the levels of bromate and bromide excreted in the urine were observed.

Other investigators have reported a much longer half-life of bromide in tissues of male Wistar rats that received 50 µg/g sodium bromate (^82^Br) in the drinking water ad libitum for up to 17 days (Pavelka et al., 2000a). Tissues were collected at time intervals of 12 to 396 hours after exposure. Half-lives ranged from 94.3 ± 14.6 hours in thyroid gland to 235.0 ± 88.9 hours in liver. The animals excreted approximately 5% of the administered bromate (^82^Br) dose 24 hours after treatment and the majority (75%) was excreted in urine (Pavelka et al., 2000b).

Absorption of sodium bromate has been studied following dermal application. Sodium bromate, formulated in a cosmetic hair neutralizer, was applied to excised guinea pig skin (0.2 mL of neutralizer containing 16.5 mg of bromate spread over 1.77 cm^2^ of skin) for 15 or 30 minutes using glass diffusion cells and 5 mL of buffered solution (CIREP, 1994). The maximum amount of bromine absorbed by the skin after a 30-minute exposure (measured as bromide) was 0.12%. In an in vivo study using albino guinea pigs, 0.5 mL of hair neutralizer containing 10.17% sodium bromate was spread over a 5 cm^2^ area of shaved skin and left on the skin for 15 minutes before rinsing the area with water (CIREP, 1994). Blood and urine samples were collected for 4 hours after exposure and analyzed for bromate using ion chromatography. No bromate was measured in the blood or urine of treated animals. The limit of detection for the analytical method was 76 ppb.

Small amounts of bromine (1 to 2 ppm) were detected in the adipose tissue of mice, but not of rats, fed bread treated with potassium bromate in a lifetime study (Kurokawa et al., 1990).

In vitro studies indicate that liver and kidney homogenates and red blood cells from male Wistar rats degrade bromate to bromide when incubated at 37° C for 30 minutes and that glutathione is probably involved in that degradation (Tanaka et al., 1984).

### Humans

Lichtenberg et al. (1989) described the clinical course of a 2-year-old male (13 kg) with acute bromate poisoning. The child had ingested 1 to 2 ounces of a permanent wave solution containing 10 to 12 g bromate/100 mL. Serum bromide levels peaked 12 hours after ingestion. The amount of bromide recovered from dialysate and urine was 1,850 mg.

Parker and Barr (1951) reported that no bromide or bromine was released following incubation of normal human gastric juice with potassium bromate at 38° C for 3 days. The authors concluded that bromate is absorbed from the stomach unchanged.

## Toxicity

### Experimental Animals

The LD_50_ for intraperitoneal injection of sodium bromate was 50 to 200 mg/kg in rats and 140 mg/kg in mice (CIREP, 1994; HSDB, 2003). The oral LD_50_ of potassium bromate in the rat was 200 to 400 mg/kg, and the LD_100_ was 700 mg/kg. A single intragastric dose of potassium bromate was administered to F344 rats, B6C3F_1_ mice, and Syrian golden hamsters (five/sex per group; Kurokawa et al., 1990). Two-thirds of the animals in all species receiving 700 to 900 mg/kg died within 3 hours. The remaining animals receiving these doses died within 48 hours. LD_50_ values were higher for females than for males in all species and ranged from 280 mg/kg for male mice to 495 mg/kg for female rats.

Kurata et al. (1992) administered single intragastric doses of 0, 50, 300, 600, and 1,200 mg potassium bromate/kg body weight to 6-week-old male F344/NCr rats. All rats treated with 1,200 mg/kg and four of five rats treated with 600 mg/kg died within 24 hours. Significant increases in relative kidney weights and proximal tubule necrosis were observed in these rats.

The effects of potassium bromate on renal function and morphology were studied in male Wistar rats given a single intraperitoneal injection of 50, 75, or 125 mg/kg (Giri et al., 1999). Examination of kidneys revealed a proliferative response and renal damage as was evident by a dose-dependent increase in ornithine decarboxylase activity, increased ^3^H-thymidine incorporation into DNA, depletion of renal glutathione and glutathione reductase activity, and increased blood urea nitrogen and serum creatinine levels. It was concluded that potassium bromate induces oxidative damage through the generation of reactive oxygen species, which results in renal cell proliferation and renal damage.

The potential effects of sodium bromate on the immune system were evaluated by the National Toxicology Program (VCU, 2000; Guo et al., 2001). Sodium bromate was administered to female B6C3F_1_ mice in drinking water for 28 days at doses of 80, 200, 400, 600, and 800 mg/L. No significant differences from those of the control group were observed in body weights, body weight gains, or the weights of thymus, liver, kidney, or lung of exposed groups. However, animals exposed to sodium bromate had significant increases in absolute (28%) and relative (26%) spleen weights. The erythrocyte counts, hemoglobin, hematocrit, mean cell volume, platelet count, total leukocyte count, and counts of differential leukocytes were unaffected by exposure to sodium bromate. A dose-related increase in reticulocytes was observed following exposure to sodium bromate with the greatest increase (78%) observed at 800 mg/L. Overall, there were no changes in the absolute number of total T cells, CD4^+^CD8^−^ T cells, CD4^−^CD8^+^ T cells, natural killer cells, or macrophages. Exposure to sodium bromate did not affect the percentage of B cells. There was no alteration in IGM antibody-forming cell response, mixed leukocyte reaction, or natural killer cell activity after exposure to sodium bromate. When the activity of peritoneal macrophages, unstimulated or stimulated with IFN-gamma and LPS, was evaluated using the cytotoxic/cytostatic assay of B16F10 tumor cells, the suppressive effect of macrophages on the proliferation of B16F10 tumor cells was decreased after exposure to sodium bromate. Sodium bromate produced minimal toxicological and immunotoxic effects in female B6C3F_1_ mice.

Accumulation of α2u-globulin and the induction of cell proliferation were examined in kidneys of rats exposed to potassium bromate, potassium bromide, or sodium bromate in the drinking water (Umemura et al., 1993). Hyaline droplets observed after exposure to potassium or sodium bromate in male rats were immunostained positive for α2u-globulin. Increases in cell proliferation were found in the proximal tubules of male rats given potassium or sodium bromate but not potassium bromide after 2, 4, and 8 weeks. Similar changes were not observed in female rats or in the distal tubules of any treated rats.

The subchronic effects of potassium bromate were evaluated by Kurokawa et al. (1990). Potassium bromate was administered in the drinking water at concentrations of 0, 150, 300, 600, 1,250, 2,500, 5,000, or 10,000 mg/L to male and female F344 rats (10/sex per group) for 13 weeks. All animals exposed to greater than 1,250 mg/L died within 7 weeks. Significant inhibition of body weight gain was observed in males exposed to 600 or 1,250 mg/L. Significant increases in serum enzyme levels (glutamate oxaloacetate transaminase, glutamate pyruvate transaminase, lactate dehydrogenase, alkaline phosphatase, blood urea nitrogen, Na^+^, and cholinesterase) were observed in males and females at 600 mg/L. Various-sized droplets and regenerative changes were observed in the renal tubules of treated males.

Male Wistar rats were exposed to 0.04% potassium bromate in the drinking water for up to 15 months (Nakano et al., 1989). Body weight gain was significantly inhibited in treated animals. Pyknotic foci were observed in the tubules of the inner medulla of the kidneys at 7 to 11 weeks. Blood urea nitrogen was increased after 15 months.

Groups of 10 male and 10 female B6C3F_1_ mice were given 250, 500, 1,000, 2,000, or 4,000 mg/L potassium bromate in the drinking water for 10 weeks (Kurokawa et al., 1990). Doses greater than 2,000 mg/L were not palatable. No treatment-related deaths were observed at doses less than 1,000 mg/L, and no histopathologic changes were attributed to potassium bromate administration.

The sensitization potential of 10.17% aqueous solution full strength sodium bromate was evaluated using the Buehler method in guinea pigs (CIREP, 1994). Only five of 19 guinea pigs had any signs of sensitization of Grade 1 irritation at 24 hours and only two of five animals had reactions at 24 hours. The authors concluded that the undiluted formulation of sodium bromate was a mild sensitizer.

### Humans

Several cases of acute bromate intoxication have been reported in humans following accidental or suicidal ingestion of permanent hair wave neutralizing solution. These products usually contain either 2% potassium bromate or 10% sodium bromate. Bromate intoxication leads to gastrointestinal symptoms (abdominal pain, nausea, vomiting, diarrhea), central nervous system depression, renal failure, and hearing loss. Bromate intoxication has been reported to be lethal (Kitto and Dumars, 1949; Matsumoto et al., 1980).

Kidney effects are frequently observed in children and adults following acute exposure with sodium and potassium bromate and include anuria, oliguria, and renal failure (Kitto and Dumars, 1949; Quick et al., 1975; Matsumoto et al., 1980; Gradus et al., 1984; Kutom et al., 1990; Watanabe et al., 1992). A review of bromate kidney toxicity found that renal failure occurred in 26 of 31 reported cases (Matsumoto et al., 1980). Histological examination of renal biopsies from children with renal effects indicated interstitial edema, tubular atrophy and dilation, interstitial fibrosis, and epithelial separation of the proximal tubules (Quick et al., 1975; Watanabe et al., 1992).

Bromate exposure produces irreversible deafness in children and adults. Quick et al. (1975) described a 6-year-old boy who ingested approximately 0.5 grams of 95% pure potassium bromate pellets. The serum bromide level of this patient was 17 mg/100 mL. Gradus et al. (1984) described a 17-month-old girl who ingested an unknown amount of permanent wave neutralizer solution containing potassium bromate. Both children developed vomiting, diarrhea, and anuria. Audiographic examinations indicated that the children had severe bilateral hearing loss. Matsumoto et al. (1980) reported two cases of women who ingested 10 and 15 grams of potassium bromate, respectively, and lost their hearing within 12 hours of ingestion. A review of bromate ototoxicity by these authors found that deafness occurred in 17 of 20 cases in Japan usually 4 to 16 hours after ingestion.

## Reproductive and Developmental Toxicology

### Experimental Animals

The National Toxicology Program (1996) evaluated the potential reproductive and developmental toxicity of sodium bromate in Sprague-Dawley rats following oral administration in the drinking water. A dose range-finding study was conducted at concentrations of 0, 250, 500, 1,000, and 2,000 mg/L to select concentrations for a 35-day study. Based on exposure concentration-related body weight decreases and decreased feed and water consumption, the concentrations chosen for the 35-day drinking water study were 0, 25, 80, and 250 mg/L. One group of male rats and two groups of female rats were treated at each exposure level. One group of females was exposed from study day 1 to 34 to test for effects during conception and early gestation. The other group of females was exposed from gestation day 6 to postnatal day 1 to test for effects during late gestation and birth. Females in this group were allowed to litter, and the pups were observed through postnatal day 5. Sodium bromate resulted in no treatment-related findings in body weights, feed consumption, clinical observations, or gross or microscopic changes in the kidney, liver, spleen, testis, or epididymis. There were no changes observed in the reproductive data for the females. There was an exposure concentration-related decrease in epididymal sperm density in treated males, which was statistically significant at 250 mg/L (18%), but there were no effects on male fertility.

Sodium bromate was evaluated for potential reproductive toxicity using the multigeneration, continuous-breeding paradigm (NTP, 2001). Sodium bromate was administered to male and female Sprague-Dawley rats in drinking water at concentrations of 0, 30, 100, and 300 mg/L. Sodium bromate produced general toxicity in male and female Sprague-Dawley rats at 100 and 300 mg/L as noted by chronic progressive nephropathy and hyaline droplets in males and renal cell proliferative changes in females. Sodium bromate was not considered a reproductive toxicant as no treatment-related changes were observed in the reproductive litter data. In males, there was a 16% decrease in sperm density in the F_0_ generation. This finding was consistent with a decrease of 18% in sperm density noted in the screening study. In the F_1_ generation, the sperm density was still decreased by 8%, but the difference was not statistically significant.

### Humans

No reproductive or developmental toxicity studies of sodium bromate or potassium bromate in humans were found in the literature.

## Carcinogenicity

### Experimental Animals

Male and female F344 rats (53/sex per group) were given potassium bromate in drinking water at concentrations of 0, 250, or 500 mg/L for 110 weeks (Kurokawa et al., 1982, 1983a). The 500 mg/L concentration was reduced to 400 mg/L during week 60 as a result of a decrease in body weight gain in male rats. The incidences of renal cell tumors (adenomas and adenocarcinomas) in exposed males and females and peritoneal mesotheliomas in exposed males were significantly increased compared with controls. Potassium bromate induced high incidences of renal cell tumors that showed a dose-response relationship in both male and female F344 rats. Renal cell tumors developed in 0% (control), 56% (250 mg/L), and 80% (500 mg/L) of female rats and 6% (control), 60% (250 mg/L), and 88% (500 mg/L) of male rats.

Dose response-studies on the carcinogenicity of potassium bromate were then conducted (Kurokawa et al., 1986a). Male F344 rats were given 0, 15, 30, 60, 125, 250, or 500 mg/L potassium bromate in drinking water for 104 weeks. The combined incidence of renal adenomas or adenocarcinomas was significantly increased in a dose-related manner in male rats exposed to 125, 250, or 500 mg/L. The incidences of thyroid gland follicular adenoma or adenocarcinoma (combined) and of peritoneal mesotheliomas were significantly increased in the 500 mg/L group.

To assess the time-course of renal tumor induction, male F344 rats were given 500 mg/L potassium bromate in drinking water for up to 104 weeks (Kurokawa et al., 1987a). In one study, administration of potassium bromate was stopped at week 13, 26, 39, 52, or 104, and rats were killed immediately. Renal adenomas were detected as early as 26 weeks. The incidences of renal dysplastic foci, adenomas, and adenomas or adenocarcinomas combined were significantly increased over controls by 52 weeks of treatment. The incidences of thyroid gland follicular adenomas, adenomas or adenocarcinomas (combined), and peritoneal mesotheliomas were significantly increased in rats receiving potassium bromate for 104 weeks. In another study, male F344 rats were given drinking water containing 500 mg/L potassium bromate for 13, 26, 39, or 52 weeks and maintained on drinking water alone until sacrifice at week 104. The incidences of renal dysplastic foci, adenomas, and adenomas or adenocarcinomas combined in rats exposed for 13 to 52 weeks were equal to or greater than those in rats continuously exposed to potassium bromate for 104 weeks.

Female B6C3F_1_ mice were exposed to 500 or 1,000 mg/L potassium bromate in drinking water for 78 weeks and thereafter given tap water for 26 weeks (Kurokawa et al., 1986b). Mice were killed at week 104. No significant differences in tumor incidences were observed between treated and control groups. In a subsequent study, 750 mg/L potassium bromate was administered orally to male B6C3F_1_, BDF_1_, and CDF_1_ mice for 88 weeks. Significant increases in the numbers of small intestine adenomas in CDF_1_ mice and liver adenomas in B6C3F_1_ mice were observed (Kurokawa et al., 1990).

More recently, male F344/N rats and B6C3F_1_ mice were given potassium bromate in drinking water at concentrations of 0, 0.02, 0.1, 0.2, or 0.4 g/L (rats) and 0, 0.08, 0.4, or 0.8 g/L (mice) for up to 100 weeks (DeAngelo et al., 1998). For rats, the incidences of renal cell tumors and thyroid gland follicular tumors were significantly increased in the 0.4 g/L group. In addition, the incidences of mesotheliomas were significantly increased in the 0.1, 0.2, and 0.4 g/L groups. For mice, the incidence of renal cell tumors was significantly increased in the 0.08 g/L group, but the higher exposure groups did not exhibit an increased incidence of renal cell tumors when compared to the control groups (control, 0/40; 0.08 g/L, 5/38; 0.4 g/L, 3/41; 0.8 g/L, 1/44). To investigate the time- and dose-dependent development of potassium bromate-induced tumors in male F344 rats, potassium bromate was dissolved in the drinking water at nominal concentrations of 0, 0.02, 0.1, 0.2, and 0.4 g/L and given for 12, 26, 52, 78, or 100 weeks (Wolf et al., 1998). Thyroid gland follicular tumors were seen as early as 26 weeks in one rat each from the 0.1 and 0.2 g/L groups. Renal cell tumors and mesotheliomas were seen in the 0.4 g/L group after 52 and 78 weeks of treatment, respectively.

The carcinogenic potential of potassium bromate was also studied in Syrian golden hamsters (Takamura et al., 1985). Groups of 20 male hamsters received 125, 250, 500, or 2,000 mg/L potassium bromate in drinking water for 89 weeks. Renal cell tumors developed in the three highest exposure groups but the incidences were not statistically significant. Because this species rarely develops spontaneous renal tumors, the authors concluded that potassium bromate has the potential to induce renal tumors in the golden hamster.

Potassium bromate was tested in two-stage carcinogenesis assays to determine whether it was able to initiate or promote carcinogenesis. Male F344 rats were given 500 or 1,000 mg/L N-ethyl-N-hydroxyethylnitrosamine (EHEN) in drinking water as an initiator for 2 weeks and then given 500 mg/L potassium bromate in drinking water as a promoter for 24 weeks. All animals were killed during week 26. Average numbers of dysplastic foci and renal cell tumors were significantly increased in male rats given potassium bromate after initiation with EHEN. The authors concluded that potassium bromate was able to initiate and promote renal carcinogenesis (Kurokawa et al., 1983b). In contrast, initiating activity was not observed when male F344/NCr rats (29 or 39 per group) were given a single intragastric dose of 300 mg/kg potassium bromate (Kurata et al., 1992). Two weeks after potassium bromate treatment, the animals were maintained on a basal diet or a diet containing 4,000 ppm sodium barbital as a promoting agent. A single oral dose of potassium bromate did not initiate renal tumors within a 104-week observation period.

Dose-response studies were conducted to investigate the enhancing effect of potassium bromate on renal carcinogenesis initiated by EHEN (Kurokawa et al., 1985). EHEN (500 ppm) was given to 6-week-old male F344 rats in drinking water for 2 weeks followed by 15, 30, 60, 120, 250, or 500 mg/L potassium bromate in drinking water for 24 weeks. Additional groups initiated with EHEN were given potassium bromide in drinking water at concentrations of 350 or 1,750 mg/L for 24 weeks. The numbers of dysplastic renal foci per cm^2^ were significantly increased in an exposure concentration-related manner from 30 mg/L to 500 mg/L. The numbers of renal cell tumors per cm^2^ were significantly increased in the 500 mg/L group. It was concluded that the threshold concentration of potassium bromate for the enhancement of renal carcinogenesis was between 15 and 30 mg/L. No enhancement of renal carcinogenesis was observed with potassium bromide.

Potassium bromate was tested for promoting and complete carcinogenic activities in skin carcinogenesis studies using Sencar mice (Kurokawa et al., 1984). Potassium bromate (8 mg in 0.2 mL of acetone) was applied to the dorsal skin of mice twice a week for 51 weeks to determine if it was a complete carcinogen. In the promotion studies, mice received a single topical application of 7,12-dimethylbenz(a)anthracene (20 nmol in 0.2 mL acetone) and potassium bromate (8 mg in 0.2 mL of acetone) was applied to initiated skin twice a week for 51 weeks. No skin tumors developed in either bromate-treated group. The authors concluded that potassium bromate is not a skin carcinogen or a promoter of skin cancer in Sencar mice.

The carcinogenicity of potassium bromate was tested in newborn F344 rats and ICR mice (Matsushima et al., 1986). Male and female rats and mice (24 hours old) were given single subcutaneous injections of potassium bromate or four weekly injections until weaning for total doses in the range of 12.5 to 800 mg/kg body weight. Rats were sacrificed at 82 weeks and mice were sacrificed at 78 weeks. No significant differences in the incidences of tumors in male or female rats or mice were observed.

Carcinogenicity studies were conducted in male and female Wistar rats and Theiller strain mice by feeding animals diets containing bread made from flour treated with 0, 50, or 75 ppm potassium bromate for 104 and 80 weeks, respectively (Fisher et al., 1979; Ginocchio et al., 1979). No carcinogenic effects were produced in rats or mice.

### Humans

No epidemiology studies of sodium bromate or potassium bromate in humans were found in the literature.

## Genetic Toxicity

There is little published mutagenicity data for sodium bromate. In an abstract that presented a brief description of test results, but no data, Eckhardt et al. (1982) reported negative results with sodium bromate in a Salmonella typhimurium mutagenicity assay and a sex-linked recessive lethal assay in male Drosophila melanogaster. However, these same authors reported dose-dependent increases in micronuclei in mouse bone marrow cells following exposure to sodium bromate (no experimental details were provided).

There is a more extensive literature describing the mutagenic activity of potassium bromate, including reports of positive results in Salmonella mutagenicity assays using base-pair substitution strains TA100, TA102, and TA104 in the presence of exogenous metabolic activation enzymes (Ishidate et al., 1984; Kurokawa et al., 1990) or the frame-shift strain TA97, with and without S9 (Zeiger et al., 1992), as well as induction of chromosomal aberrations, micronuclei, DNA strand breaks, oxidative DNA base damage, and HPRT gene mutations in cultured Chinese hamster fibroblast cells (Ishidate et al., 1984; Speit et al., 1999). Acute in vivo studies with potassium bromate demonstrated dose-related increases in the frequencies of chromosomally aberrant metaphases in bone marrow cells of rats treated by gavage or intraperitoneal injection (Fujie et al., 1988). In addition, potassium bromate was reported to induce micronuclei in polychromatic erythrocytes of rats treated by intraperitoneal injection (Sai et al., 1992a) and of mice treated by gavage (Hayashi et al., 1988, 1989; Nakajima et al., 1989) or intraperitoneal injection (Hayashi et al., 1988; Awogi et al., 1992). It has been proposed that the mechanism for bromate genotoxicity in these test systems involves metabolic generation of reactive intermediates (Kurokawa et al., 1990) in the form of bromine radicals (Ballmaier and Epe, 1995; Speit et al., 1999) rather than reactive oxygen species.

## Background on Genetically Altered Mice

Mutation and/or deletions of tumor suppressor genes or activation of protooncogenes can disrupt cell function and predispose an animal to cancer. In the current studies, two genetically altered mouse models with either a loss of heterozygosity in a critical cancer gene (Trp53) or a gain of oncogene function (Ha ras) were used to determine how these animals would respond to sodium bromate exposure. These mouse models are susceptible to the rapid development of cancer. The Tg.AC hemizygous and p53 haploinsufficient mice are being evaluated by the National Institute of Environmental Health Sciences (NIEHS) and the NTP as models for identifying chemical toxicity and/or chemical carcinogenic processes (Tennant et al., 1996; Pritchard et al., 2003).

### FVB/N-TgN(v-Ha-ras)Led (Tg.AC) Hemizygous Mouse Model

Tg.AC mice are hemizygous for a mutant v-Ha-ras transgene. The Tg.AC hemizygous mouse (on an FVB/N background) was developed by Leder et al. (1990) by introduction via pronuclear injection of a tripartite transgene composed of the promotor of the mouse embryonic zeta-globin gene, through the v-Ha-ras coding sequence, with point mutations in codons 12 and 59, and an SV40 polyadenylation sequence. Because the inducible zeta-globin promoter drives the expression of a mutated v-Ha-ras oncogene, the Tg/AC mouse is regarded as a genetically initiated model.

The Tg.AC transgenic mouse model has been evaluated as a reporter phenotype (skin papillomas) in response to either genotoxic or nongenotoxic carcinogens, including tumor promoters (Spalding et al., 1993, 1999; Tennant et al., 1999). With the exception of bone marrow, constitutive expression of the transgene cannot be detected in adult tissues. The transgene is transcriptionally silent until activated by certain treatments including full-thickness wounding, ultraviolet irradiation, or exposure to some chemicals (Cannon et al., 1997; Trempus et al., 1998). The Tg.AC hemizygous mouse develops a high incidence of skin papillomas in response to topical application of 12-O-tetradecanoyl-phorbol-13-acetate (TPA), and TPA has been used as a positive control in NIEHS Tg.AC mouse studies (Spalding et al., 1993). TPA has been used a a positive control in NIEHS Tg.AC mouse studies to confirm the mice are responsive to carcinogens because it has been found that a subset of Tg.AC mice may revert and become nonresponsive to a tumor promoter (Honchel et al., 2001). Point mutations in the Ha-ras gene are believed to be early events in the induction of skin papillomas and malignancies. Topical application of carcinogens to the shaved dorsal surface of Tg.AC mice induces epidermal squamous cell papillomas or carcinomas, a reporter phenotype that defines the activity of the chemical. The oral route of administration can also generate tumor responses in the skin of Tg.AC mice and lead to squamous cell papillomas and/or carcinomas of the forestomach. To date, the appearance of either spontaneous or induced tumors has been shown to involve transgene expression. However, the mechanism of response by the Tg.AC model to chemical carcinogens is not yet understood.

In NIEHS studies, mice are exposed beginning at 2 months of age for a total of 6 to 9 months. Cutaneous papillomas at various sites have been reported at 10% and 7% incidence in 33-week-old control male and female Tg.AC mice, respectively (Mahler et al.,1998). Cutaneous papillomas occurring at sites such as the lip, pinnae, prepuce, and vulva suggest a possible relationship to grooming and chronic irritation. Up to 32% of Tg.AC homozygous and heterozygous male or female mice develop odontogenic tumors as early as 33 weeks (Wright et al., 1995; Mahler et al., 1998). A number of different tumor types occur in untreated Tg.AC hemizygous mice at an incidence of greater than 3% including odontogenic tumors, forestomach papillomas, cutaneous papillomas, alveolar/bronchiolar adenomas, salivary gland duct carcinomas, and erythroleukemia (Mahler et al.,1998). In the FVB mouse (the background strain for the Tg.AC hemizygous mouse), alveolar/bronchiolar neoplasms occur at 14 months of age (Mahler et al., 1996).

The Tg.AC hemizygous mouse model was used in the current report for the studies of sodium bromate because this model has been reported to detect both nongenotoxic and genotoxic carcinogens (Spalding et al., 1993; Tennant et al., 1995, 1996; Pritchard et al., 2003).

### B6.129-Trp53^tm1Brd^ (N5) Haploinsufficient Mouse Model

The heterozygous B6.129-Trp53 (N12)^tm1Brd(+/−)^ mouse (on a B6.129S7 background) was developed by Donehower et al. (1992). A null mutation was introduced into one p53 allele by homologous recombination in murine embryonic stem cells. Insertion of a neo cassette resulted in deletion of a 450-base pair gene fragment containing 106 nucleotides of exon 5 and approximately 350 nucleotides of intron 4.

Trp53, a nuclear protein, plays an essential role in the regulation of the cell cycle, specifically in the transition from G_0_ to G_1_, as well as G_2_ to M, and the spindle apparatus. The p53 protein has a short half-life and exists at a very low concentration under normal cell physiological conditions. However, in DNA damaged cells that are able to replicate, p53 is expressed in high amounts with a significant increase in half-life due to posttranslational modification (phosphorylation or acetylation). Mutation in p53 may also increase the protein half-life and alter the functions that may contribute to transformation and development of the malignant phenotype. p53 is a DNA-binding protein containing DNA-binding, oligomerization, and transcription activation domains. Many amino acid residues in different p53 domains may be phosphorylated or acetylated, which may determine specific p53 functions. It is postulated to bind as a tetramer to a p53-binding site and activate expression of downstream genes that inhibit growth and/or invasion or promote apoptosis, functioning as a tumor suppressor. This protein is critical to tumor suppression in humans and rodents. Mutants of p53 that fail to bind the consensus DNA binding site, and hence are unable to function as tumor suppressors, frequently occur in human cancers. Alterations of the Tp53 gene occur not only as somatic mutations in human malignancies, but also as germ line mutations in some cancer-prone families with Li-Fraumeni syndrome.

The mouse heterozygous for a p53 null allele (+/−) has only a single functional wild-type p53 allele which provides a target for mutagens. The p53 tumor suppressor gene is one of the most common sites for mutations and gene alterations in human cancer (Harris, 1996a,b,c)

Heterozygous p53^(+/−)^ mice develop normally, and like humans and other mammals, develop cancer (primarily lymphomas or sarcomas) with age, but often with decreased latency.

## Study Rationale

Sodium bromate was nominated for toxicity and carcinogenicity studies in genetically modified mouse models by the United States Environmental Protection Agency and the National Institute of Environmental Health Sciences. Sodium bromate is a drinking water disinfection by-product formed during the ozonation of source water containing bromide. The objective of this study was to determine whether the use of genetically modified mice could reduce study length while being more effective at determining potential hazards of drinking water disinfection by-products compared to traditional rodent bioassays. Given the hundreds of potentially hazardous disinfection by-products (Bull et al., 1995), usually at very low concentrations and occurring as mixtures, a more efficient process for determining safety of chemicals and chemical mixtures found in finished drinking water is needed.

This report focuses on Tg.AC hemizygous and p53 haploinsufficient strains that were exposed to sodium bromate in the drinking water for up to 43 weeks. The Tg.AC hemizygous mouse strain was also exposed to sodium bromate by the dermal route, which if predictive, could prove to be the most efficient screening procedure for drinking water mixtures.