# APPENDIX H WATER AND COMPOUND CONSUMPTION IN THE 27- AND 43-WEEK DRINKING WATER STUDIES OF SODIUM BROMATE

TABLE H1 Water and Compound Consumption by Male Tg.AC Hemizygous Mice in the 27-Week Drinking Water Study of Sodium Bromate

Week | 0 mg/L | | 80 mg/L | | | 400 mg/L | | | 800 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
2 | 6.0 | 24.1 | | | | 6.2 | 24.0 | 104 | 5.0 | 23.9 | 166
3 | 5.8 | 26.2 | 5.4 | 26.4 | 16 | 4.2 | 26.0 | 64 | 4.6 | 25.3 | 144
4 | 4.8 | 27.6 | | | | 4.7 | 27.4 | 69 | 5.8 | 26.9 | 173
5 | 6.4 | 28.3 | 5.7 | 29.1 | 16 | 4.5 | 28.6 | 63 | 5.0 | 27.4 | 147
6 | 5.5 | 29.7 | 4.9 | 30.0 | 13 | 5.1 | 29.3 | 70 | 4.0 | 28.0 | 115
7 | | | 5.5 | 30.7 | 14 | 4.9 | 29.9 | 65 | 5.8 | 28.6 | 161
8 | 6.2 | 31.7 | 4.3 | 31.3 | 11 | 5.5 | 30.4 | 72 | 5.2 | 28.7 | 144
9 | 5.3 | 32.6 | 4.7 | 32.4 | 12 | 5.0 | 31.4 | 63 | 5.3 | 29.6 | 144
10 | 7.3 | 33.3 | 5.8 | 33.0 | 14 | 5.0 | 31.7 | 63 | 4.7 | 29.2 | 129
11 | 5.4 | 34.9 | 5.8 | 34.5 | 13 | 5.2 | 32.3 | 64 | 5.6 | 30.1 | 150
12 | 5.4 | 35.9 | 5.0 | 35.0 | 11 | 6.7 | 33.1 | 81 | 4.7 | 30.8 | 121
13 | 4.5 | 36.5 | 4.8 | 35.9 | 11 | 6.2 | 34.2 | 73 | 4.9 | 31.1 | 126
14 | 4.6 | 36.5 | 5.3 | 36.2 | 12 | 4.8 | 33.6 | 57 | 4.2 | 30.6 | 109
15 | 5.0 | 36.3 | 5.7 | 35.8 | 13 | 5.4 | 35.0 | 62 | 4.8 | 31.7 | 121
16 | 5.2 | 35.7 | | | | | | | 4.9 | 31.7 | 124
17 | 4.8 | 35.8 | 6.6 | 35.6 | 15 | | | | 3.9 | 31.0 | 100
18 | 5.4 | 36.2 | 5.7 | 35.8 | 13 | 5.1 | 33.0 | 62 | 4.5 | 30.8 | 116
19 | 5.5 | 36.2 | 4.6 | 35.4 | 10 | 3.7 | 33.3 | 44 | 4.0 | 30.6 | 105
20 | 4.9 | 36.4 | 6.9 | 36.0 | 15 | 4.1 | 33.1 | 50 | 3.4 | 31.2 | 87
21 | 5.0 | 36.6 | 5.7 | 36.6 | 13 | 4.1 | 33.6 | 48 | 5.5 | 31.2 | 87
22 | 4.7 | 37.1 | 5.5 | 37.0 | 12 | 5.7 | 33.9 | 68 | 5.4 | 31.5 | 136
23 | 4.7 | 36.4 | 5.2 | 37.2 | 11 | 5.6 | 33.3 | 67 | 4.5 | 30.9 | 115
24 | 5.2 | 37.0 | 5.0 | 37.6 | 11 | 4.7 | 34.3 | 54 | 4.2 | 31.1 | 108
25 | 5.1 | 36.2 | 4.4 | 37.6 | 9 | 3.6 | 33.9 | 42 | 4.4 | 31.7 | 111
26 | 4.9 | 38.0 | 4.0 | 37.1 | 9 | 4.0 | 34.0 | 48 | 4.4 | 32.1 | 111
Mean for weeks
1–13 | 5.7 | 31.0 | 5.2 | 31.8 | 13 | 5.3 | 29.9 | 71 | 5.0 | 28.3 | 143
14–26 | 5.0 | 36.5 | 5.4 | 36.5 | 12 | 4.6 | 33.7 | 55 | 4.5 | 31.3 | 114

a Grams of water consumed per animal per day

b Milligrams of sodium bromate consumed per kilogram body weight per day

TABLE H2 Water and Compound Consumption by Female Tg.AC Hemizygous Mice in the 27-Week Drinking Water Study of Sodium Bromate

Week | 0 mg/L | | 80 mg/L | | | 400 mg/L | | | 800 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
2 | | | | | | 5.5 | 20.0 | 111
3 | 5.3 | 20.3 | | | | 5.4 | 21.4 | 101 | 4.7 | 21.0 | 179
4 | 6.1 | 22.6 | 5.2 | 22.9 | 18 | 4.4 | 23.2 | 75 | 4.5 | 22.4 | 160
5 | 6.2 | 23.5 | 4.5 | 23.6 | 15 | 4.8 | 24.1 | 80 | 4.3 | 22.8 | 149
6 | 5.8 | 23.8 | 5.5 | 24.0 | 18 | 5.7 | 23.8 | 95 | 4.2 | 22.4 | 148
7 | 4.5 | 25.0 | 5.0 | 24.5 | 16 | 4.2 | 24.5 | 69 | 4.6 | 23.7 | 157
8 | 5.7 | 25.3 | 5.4 | 25.3 | 17 | 5.3 | 25.1 | 85 | 4.6 | 24.1 | 154
9 | 5.1 | 26.4 | 5.4 | 26.0 | 17 | 5.6 | 25.8 | 87 | 4.7 | 25.0 | 149
10 | 5.5 | 27.6 | 5.1 | 26.4 | 15 | 5.6 | 26.2 | 85 | 4.7 | 24.3 | 155
11 | 4.9 | 28.0 | 4.8 | 26.2 | 15 | 5.1 | 26.0 | 78 | 5.0 | 25.5 | 156
12 | 5.0 | 28.4 | 5.0 | 27.2 | 15 | 5.8 | 26.7 | 86 | 4.1 | 25.5 | 128
13 | 5.3 | 28.3 | 5.4 | 27.6 | 16 | 4.6 | 26.9 | 69 | 4.8 | 25.5 | 150
14 | 5.2 | 28.4 | 4.8 | 27.7 | 14 | 4.2 | 27.3 | 61 | 4.2 | 25.6 | 133
15 | 3.8 | 28.9 | 4.3 | 27.4 | 12 | 5.0 | 27.7 | 72 | 4.3 | 26.0 | 132
16 | 3.5 | 28.7 | 5.8 | 27.7 | 17 | 4.6 | 27.2 | 68 | 5.8 | 26.2 | 178
17 | 5.4 | 29.0 | 4.6 | 27.7 | 13 | 5.1 | 27.2 | 75 | 4.4 | 25.2 | 138
18 | 4.3 | 28.7 | 3.3 | 27.4 | 10 | 5.0 | 27.8 | 71 | 5.0 | 26.1 | 152
19 | 3.4 | 28.2 | 4.8 | 28.0 | 14 | 4.2 | 28.9 | 58 | 4.2 | 25.4 | 134
20 | 4.7 | 29.1 | 5.3 | 29.0 | 15 | 4.4 | 29.2 | 61 | 5.1 | 25.8 | 159
21 | 4.6 | 29.6 | 4.9 | 29.3 | 13 | 3.9 | 29.5 | 53 | 4.0 | 25.8 | 125
22 | 4.5 | 30.9 | 5.5 | 29.7 | 15 | 4.5 | 30.3 | 59 | 5.3 | 26.6 | 159
23 | 3.5 | 29.8 | 4.5 | 29.4 | 12 | 3.7 | 30.1 | 49 | 4.6 | 26.6 | 138
24 | 3.2 | 30.6 | 4.3 | 29.4 | 12 | 3.4 | 31.0 | 44 | 4.4 | 26.2 | 136
25 | 3.3 | 31.4 | 3.6 | 29.8 | 10 | 4.0 | 31.2 | 51 | 4.3 | 26.6 | 130
26 | 3.8 | 31.2 | 4.3 | 30.5 | 11 | 3.1 | 31.8 | 39 | 4.3 | 26.5 | 129
Mean for weeks
1–13 | 5.4 | 25.4 | 5.1 | 25.4 | 16 | 5.2 | 24.5 | 85 | 4.6 | 23.8 | 153
14–26 | 4.1 | 29.6 | 4.6 | 28.7 | 13 | 4.2 | 29.2 | 59 | 4.6 | 26.0 | 142

a Grams of water consumed per animal per day

b Milligrams of sodium bromate consumed per kilogram body weight per day

TABLE H3 Water and Compound Consumption by Male Tg.AC Hemizygous Mice in the 43-Week Drinking Water Study of Sodium Bromate

Week | 0 mg/L | | 80 mg/L | | | 400 mg/L | | | 800 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
2 | 4.3 | 24.4 | 4.2 | 24.3 | 14 | 4.3 | 24.8 | 69 | 6.2 | 23.2 | 214
3 | 5.3 | 25.9 | 5.0 | 25.0 | 16 | 4.7 | 26.1 | 73 | 5.0 | 24.1 | 167
4 | 4.7 | 28.2 | | | | 4.6 | 28.4 | 64 | 6.2 | 25.8 | 191
5 | 5.7 | 29.0 | | | | 5.0 | 29.3 | 68 | 4.6 | 27.4 | 135
6 | 5.9 | 29.4 | | | | 4.7 | 30.6 | 62 | 4.3 | 28.7 | 119
7 | 5.7 | 30.9 | 4.0 | 31.7 | 10 | 5.6 | 30.8 | 73 | 5.1 | 29.4 | 138
8 | 5.8 | 32.1 | 6.0 | 32.4 | 15 | 6.4 | 31.8 | 80 | 4.4 | 29.7 | 119
9 | 5.5 | 32.5 | 5.8 | 33.1 | 14 | 5.9 | 32.1 | 73 | 5.3 | 30.6 | 140
10 | 6.0 | 33.4 | 4.9 | 34.2 | 11 | 5.7 | 32.6 | 69 | 4.8 | 30.5 | 127
11 | 4.9 | 33.3 | 7.1 | 33.9 | 17 | 5.1 | 32.8 | 62 | 4.2 | 30.1 | 113
12 | 4.0 | 34.3 | 6.1 | 35.0 | 14 | 4.6 | 33.2 | 56 | 4.6 | 30.3 | 121
13 | 3.7 | 35.1 | 5.5 | 36.0 | 12 | 5.1 | 33.9 | 60 | 5.1 | 30.7 | 133
14 | 3.9 | 35.6 | 4.8 | 36.5 | 10 | 5.1 | 34.2 | 60 | 5.1 | 30.4 | 135
15 | 4.3 | 36.2 | 4.5 | 37.5 | 10 | 4.9 | 34.9 | 56 | 4.9 | 30.4 | 129
16 | 3.9 | 34.8 | 6.7 | 36.7 | 14 | 3.9 | 33.9 | 46 | 4.9 | 30.2 | 131
17 | 4.9 | 36.2 | 5.5 | 37.1 | 12 | 4.7 | 34.3 | 55 | 3.8 | 31.4 | 98
18 | 5.6 | 36.8 | 6.9 | 37.7 | 15 | 4.1 | 34.8 | 47 | 5.0 | 31.6 | 128
19 | 3.9 | 36.7 | 5.4 | 36.3 | 12 | 5.2 | 34.5 | 60 | 4.9 | 32.1 | 122
20 | 4.7 | 36.8 | 4.3 | 37.6 | 9 | 4.3 | 35.8 | 48 | 4.4 | 32.6 | 108
21 | 4.8 | 37.1 | 3.8 | 37.2 | 8 | 4.6 | 36.0 | 51 | 5.2 | 32.2 | 130
22 | 5.6 | 38.1 | 3.5 | 37.2 | 8 | 5.0 | 36.0 | 56 | 5.5 | 32.1 | 137
23 | 4.4 | 37.8 | 4.2 | 36.7 | 9 | 4.5 | 36.5 | 49 | 5.8 | 31.4 | 147
24 | 3.9 | 37.8 | 3.6 | 36.6 | 8 | 4.5 | 35.6 | 50 | 4.7 | 31.4 | 121
25 | 5.1 | 37.7 | 3.8 | 36.5 | 8 | 3.9 | 35.8 | 44 | 5.2 | 31.6 | 132
26 | 4.3 | 38.7 | 4.3 | 37.5 | 9 | 4.0 | 36.2 | 44 | 4.6 | 32.2 | 114
27 | 3.4 | 38.3 | 4.0 | 37.4 | 8 | 4.8 | 35.8 | 54 | 4.2 | 32.3 | 104
28 | 4.4 | 39.6 | 3.6 | 37.2 | 8 | 4.9 | 38.8 | 50 | 3.8 | 33.0 | 91
29 | 4.7 | 39.2 | 4.7 | 40.2 | 9 | 3.8 | 37.5 | 41 | 4.3 | 32.7 | 106
30 | 3.9 | 38.4 | 4.7 | 39.5 | 10 | 4.1 | 37.2 | 44 | 4.1 | 32.9 | 99
31 | 4.4 | 38.0 | 7.0 | 40.2 | 14 | 3.4 | 37.6 | 37 | 4.1 | 32.5 | 100
32 | 4.7 | 37.9 | 4.7 | 39.9 | 9 | 4.2 | 37.8 | 45 | 3.8 | 33.1 | 92
33 | 3.6 | 39.3 | 5.5 | 40.9 | 11 | 3.9 | 38.1 | 41 | 4.8 | 33.6 | 115
34 | 4.1 | 39.1 | 6.2 | 40.8 | 12 | 3.3 | 37.0 | 35 | 4.9 | 33.6 | 117
35 | 4.3 | 42.7 | 3.9 | 41.2 | 8 | 2.8 | 37.7 | 30 | 4.9 | 32.3 | 120
36 | 4.2 | 42.6 | 5.0 | 41.9 | 10 | 3.4 | 37.7 | 36 | 4.8 | 32.5 | 117
37 | 6.4 | 42.5 | 6.9 | 41.7 | 13 | 3.4 | 39.6 | 35 | 5.0 | 32.3 | 123
38 | 3.5 | 42.6 | 6.7 | 41.0 | 13 | 3.3 | 39.3 | 34 | 5.8 | 30.6 | 152
39 | 4.2 | 43.2 | 3.8 | 42.7 | 7 | 4.2 | 38.6 | 43 | 5.3 | 30.1 | 140
40 | 3.9 | 43.8 | 4.7 | 42.0 | 9 | 4.5 | 39.1 | 46 | 6.1 | 29.0 | 168
41 | 3.0 | 43.0 | 5.7 | 42.2 | 11 | 5.0 | 40.7 | 49 | 6.5 | 29.0 | 179
42 | 4.6 | 42.1 | 6.5 | 42.1 | 12 | 3.6 | 40.6 | 35 | 6.4 | 29.9 | 170
Mean for weeks
1–13 | 5.1 | 30.7 | 5.4 | 31.7 | 14 | 5.1 | 30.5 | 67 | 5.0 | 28.4 | 143
14–42 | 4.4 | 39.1 | 5.0 | 39.0 | 10 | 4.2 | 36.9 | 45 | 4.9 | 31.7 | 125

a Grams of water consumed per animal per day

b Milligrams of sodium bromate consumed per kilogram body weight per day

TABLE H4 Water and Compound Consumption by Female Tg.AC Hemizygous Mice in the 43-Week Drinking Water Study of Sodium Bromate

Week | 0 mg/L | | 80 mg/L | | | 400 mg/L | | | 800 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
2 | 6.4 | 19.6 | | | | | | | 4.2 | 19.3 | 175
3 | 5.2 | 20.3 | 4.6 | 20.6 | 18 | | | | 4.5 | 21.7 | 165
4 | | | | | | | | | 4.1 | 22.7 | 145
5 | 5.6 | 23.9 | 7.0 | 23.7 | 24 | 6.7 | 23.8 | 113 | 3.9 | 23.4 | 133
6 | | | 6.7 | 24.6 | 22 | 6.7 | 24.6 | 109 | 3.5 | 24.1 | 116
7 | 5.7 | 24.6 | 6.4 | 25.1 | 20 | 6.5 | 24.8 | 104 | 3.9 | 24.4 | 128
8 | 4.3 | 26.2 | | | | 4.3 | 25.7 | 66 | 3.9 | 24.9 | 125
9 | 5.1 | 25.0 | 6.0 | 26.2 | 18 | 4.3 | 25.7 | 68 | 4.0 | 25.2 | 128
10 | 5.8 | 25.6 | 6.8 | 26.3 | 21 | 3.8 | 26.0 | 58 | 3.9 | 25.1 | 123
11 | 4.5 | 25.3 | 4.9 | 26.3 | 15 | 4.5 | 25.2 | 71 | 4.2 | 24.6 | 137
12 | 4.0 | 25.8 | 5.6 | 26.6 | 17 | 4.4 | 26.2 | 67 | 3.7 | 24.6 | 120
13 | 5.0 | 25.8 | 7.1 | 27.1 | 21 | 4.3 | 27.1 | 63 | 3.8 | 24.1 | 126
14 | 4.3 | 26.1 | 5.6 | 27.4 | 16 | 5.5 | 27.0 | 81 | 3.5 | 24.0 | 118
15 | 5.3 | 27.6 | 5.4 | 28.5 | 15 | 5.2 | 27.4 | 75 | 4.9 | 25.2 | 154
16 | 5.6 | 28.5 | 3.6 | 27.4 | 11 | 3.9 | 26.8 | 58 | 5.8 | 24.6 | 187
17 | 5.2 | 28.8 | 5.2 | 28.1 | 15 | 4.7 | 28.2 | 66 | 4.9 | 24.9 | 159
18 | 5.4 | 28.9 | 4.9 | 29.2 | 14 | 6.0 | 29.0 | 83 | 6.5 | 27.0 | 193
19 | 4.6 | 30.4 | 4.3 | 29.6 | 12 | 4.6 | 30.0 | 61 | 6.3 | 26.4 | 190
20 | 4.0 | 29.5 | 5.1 | 29.7 | 14 | 4.0 | 30.1 | 54 | 6.6 | 26.4 | 200
21 | 5.1 | 30.2 | 4.9 | 30.1 | 13 | 3.9 | 29.8 | 53 | 6.1 | 26.4 | 185
22 | 3.4 | 30.5 | 5.3 | 29.7 | 14 | 6.0 | 28.3 | 84 | 5.8 | 26.5 | 175
23 | 4.6 | 29.8 | 5.7 | 29.9 | 15 | 5.0 | 28.6 | 70 | 5.7 | 25.9 | 178
24 | 4.6 | 32.1 | 5.3 | 29.5 | 14 | 5.3 | 29.9 | 70 | 4.8 | 25.2 | 151
25 | 4.9 | 31.8 | 3.3 | 29.7 | 9 | 3.2 | 30.3 | 42 | 5.4 | 25.9 | 168
26 | 4.7 | 32.1 | 4.8 | 29.5 | 13 | 5.1 | 31.7 | 64 | 4.4 | 26.0 | 135
27 | 4.8 | 33.8 | 5.4 | 29.2 | 15 | 4.6 | 32.1 | 57 | 4.5 | 26.6 | 135
28 | 4.0 | 34.0 | 4.4 | 30.3 | 12 | 5.1 | 32.8 | 62 | 3.7 | 27.1 | 110
29 | 4.3 | 34.2 | 5.1 | 29.9 | 14 | 5.6 | 33.3 | 67 | 4.1 | 26.4 | 123
30 | 4.2 | 33.4 | 4.8 | 30.0 | 13 | 4.7 | 34.2 | 55 | 4.4 | 27.2 | 128
31 | 4.5 | 33.4 | 4.1 | 29.7 | 11 | 4.7 | 34.4 | 55 | 5.4 | 27.8 | 156
32 | 4.8 | 33.6 | 5.0 | 29.8 | 13 | 4.1 | 33.6 | 49 | 5.6 | 28.3 | 160
33 | 4.6 | 34.6 | 4.5 | 29.5 | 12 | 4.4 | 34.8 | 51 | 5.3 | 28.3 | 149
34 | 4.1 | 35.3 | 4.2 | 28.9 | 12 | 4.2 | 35.2 | 48 | 4.5 | 27.4 | 131
35 | 3.5 | 34.9 | 4.4 | 28.3 | 13 | 3.7 | 34.8 | 42 | 5.2 | 28.8 | 145
36 | 3.2 | 34.8 | 4.7 | 29.7 | 13 | 4.9 | 35.6 | 54 | 4.9 | 28.3 | 139
37 | 4.9 | 35.3 | 3.8 | 29.1 | 11 | 4.8 | 36.2 | 53 | 5.2 | 28.5 | 145
38 | 4.2 | 35.1 | 5.1 | 29.4 | 14 | 4.4 | 35.6 | 50 | 5.6 | 28.7 | 155
39 | 4.2 | 34.8 | 4.1 | 29.5 | 11 | 4.1 | 35.1 | 47 | 4.7 | 26.9 | 140
40 | 4.7 | 34.7 | 4.8 | 29.8 | 13 | 2.9 | 35.1 | 33 | 5.7 | 24.0 | 191
41 | 3.9 | 33.9 | 4.6 | 29.2 | 13 | 3.6 | 33.9 | 43 | 6.3 | 23.6 | 212
42 | 4.7 | 33.6 | 4.3 | 29.4 | 12 | 4.2 | 37.8 | 44 | 6.2 | 23.1 | 215
Mean for weeks
1–13 | 5.2 | 24.2 | 6.1 | 25.2 | 19 | 5.0 | 25.5 | 80 | 4.0 | 23.7 | 135
14–42 | 4.5 | 32.3 | 4.7 | 29.3 | 13 | 4.6 | 32.1 | 58 | 5.2 | 26.4 | 159

a Grams of water consumed per animal per day

b Milligrams of sodium bromate consumed per kilogram body weight per day

TABLE H5 Water and Compound Consumption by Male p53 Haploinsufficient Mice in the 27-Week Drinking Water Study of Sodium Bromate

Week | 0 mg/L | | 80 mg/L | | | 400 mg/L | | | 800 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
2 | 3.6 | 25.0 | 3.6 | 25.7 | 11 | 3.3 | 25.6 | 52 | 3.4 | 24.6 | 110
3 | 3.6 | 26.2 | 3.5 | 26.8 | 10 | 3.4 | 27.0 | 50 | 3.2 | 25.9 | 100
5 | 3.7 | 28.4 | 3.7 | 29.3 | 10 | 3.5 | 29.5 | 47 | 3.4 | 28.2 | 97
6 | 3.5 | 29.7 | 3.4 | 30.9 | 9 | 3.4 | 31.1 | 44 | 3.2 | 29.6 | 87
7 | 3.7 | 31.3 | 3.7 | 32.8 | 9 | 3.6 | 32.7 | 44 | 3.3 | 30.9 | 86
8 | 3.7 | 32.2 | 3.5 | 33.8 | 8 | 3.4 | 34.2 | 40 | 3.3 | 31.8 | 82
9 | 4.0 | 33.5 | 3.8 | 34.9 | 9 | 3.7 | 35.4 | 42 | 3.5 | 33.3 | 84
10 | 3.8 | 35.1 | 3.5 | 36.4 | 8 | 3.5 | 36.7 | 38 | 3.1 | 34.5 | 73
11 | 3.9 | 36.4 | 3.5 | 37.7 | 8 | 3.6 | 37.9 | 38 | 3.2 | 35.5 | 72
12 | 4.1 | 37.7 | 3.6 | 38.9 | 7 | 3.6 | 39.1 | 37 | 3.2 | 36.4 | 70
13 | 4.1 | 38.7 | 3.6 | 40.0 | 7 | 3.7 | 39.9 | 37 | 3.3 | 37.4 | 70
14 | 4.0 | 39.9 | 3.5 | 40.9 | 7 | 3.5 | 40.1 | 35 | 3.2 | 38.0 | 68
15 | 4.1 | 41.2 | 3.5 | 42.2 | 7 | 3.5 | 41.3 | 34 | 3.2 | 38.8 | 67
16 | 4.2 | 41.6 | 3.7 | 43.0 | 7 | 3.7 | 41.6 | 36 | 3.3 | 39.0 | 67
17 | 4.1 | 42.2 | 3.9 | 43.3 | 7 | 3.7 | 42.2 | 35 | 3.2 | 40.7 | 62
18 | 4.2 | 43.1 | 3.9 | 44.9 | 7 | 3.8 | 42.9 | 36 | 3.4 | 41.5 | 66
19 | 4.1 | 43.6 | 3.6 | 44.9 | 6 | 3.7 | 43.3 | 34 | 3.2 | 42.0 | 61
20 | 4.2 | 44.0 | 3.9 | 45.1 | 7 | 3.8 | 45.4 | 33 | 3.4 | 42.6 | 63
21 | 4.1 | 44.4 | 3.6 | 45.7 | 6 | 4.1 | 45.8 | 36 | 3.3 | 42.8 | 62
22 | 4.3 | 44.5 | 3.9 | 46.6 | 7 | 3.9 | 46.1 | 34 | 3.5 | 43.7 | 64
23 | 4.3 | 45.3 | 3.8 | 47.4 | 6 | 3.9 | 46.4 | 34 | 3.2 | 44.4 | 57
24 | 4.2 | 45.6 | 3.9 | 47.6 | 7 | 4.2 | 46.8 | 36 | 3.4 | 45.1 | 60
25 | 3.9 | 46.3 | 3.7 | 48.0 | 6 | 4.0 | 47.4 | 34 | 3.1 | 45.7 | 54
26 | 4.4 | 46.5 | 4.1 | 48.1 | 7 | 3.9 | 47.2 | 33 | 3.4 | 45.5 | 60
Mean for weeks
1–13 | 3.8 | 32.2 | 3.6 | 33.4 | 9 | 3.5 | 33.6 | 43 | 3.3 | 31.6 | 85
14–26 | 4.2 | 43.7 | 3.8 | 45.2 | 7 | 3.8 | 44.3 | 35 | 3.3 | 42.3 | 62

a Grams of water consumed per animal per day

b Milligrams of sodium bromate consumed per kilogram body weight per day

TABLE H6 Water and Compound Consumption by Female p53 Haploinsufficient Mice in the 27-Week Drinking Water Study of Sodium Bromate

Week | 0 mg/L | | 80 mg/L | | | 400 mg/L | | | 800 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
2 | 4.0 | 20.8 | 3.9 | 20.5 | 15 | 4.0 | 20.3 | 79 | 3.9 | 20.4 | 154
3 | 4.3 | 21.4 | 3.9 | 21.2 | 15 | 4.0 | 21.1 | 77 | 3.9 | 21.0 | 148
5 | 4.5 | 22.6 | 4.4 | 22.3 | 16 | 4.5 | 21.7 | 82 | 4.3 | 22.1 | 156
6 | 4.6 | 23.0 | 4.0 | 22.8 | 14 | 4.1 | 22.2 | 75 | 4.2 | 22.4 | 148
7 | 4.3 | 23.8 | 4.1 | 23.4 | 14 | 4.3 | 22.7 | 75 | 4.1 | 23.1 | 142
8 | 4.6 | 24.2 | 4.3 | 23.8 | 14 | 4.1 | 22.9 | 72 | 4.4 | 23.1 | 153
9 | 4.8 | 24.9 | 4.2 | 24.4 | 14 | 4.6 | 23.5 | 78 | 4.3 | 23.4 | 148
10 | 4.6 | 25.6 | 3.9 | 25.2 | 12 | 4.3 | 24.2 | 72 | 3.8 | 24.0 | 128
11 | 4.9 | 26.2 | 3.9 | 25.5 | 12 | 4.4 | 24.3 | 72 | 4.2 | 24.0 | 141
12 | 4.9 | 26.2 | 4.2 | 26.0 | 13 | 4.6 | 24.8 | 74 | 4.6 | 24.2 | 152
13 | 4.8 | 27.4 | 4.4 | 26.9 | 13 | 4.8 | 24.8 | 77 | 4.6 | 24.6 | 148
14 | 4.6 | 28.0 | 4.3 | 27.1 | 13 | 4.8 | 25.9 | 75 | 4.4 | 25.1 | 141
15 | 4.6 | 28.4 | 4.2 | 27.6 | 12 | 4.9 | 26.4 | 73 | 4.7 | 25.5 | 147
16 | 4.9 | 29.3 | 4.3 | 28.4 | 12 | 4.5 | 26.9 | 67 | 4.4 | 26.1 | 135
17 | 4.6 | 30.4 | 4.1 | 29.2 | 11 | 4.7 | 27.5 | 69 | 4.2 | 26.8 | 124
18 | 4.5 | 30.2 | 4.3 | 28.9 | 12 | 4.6 | 27.7 | 67 | 4.2 | 27.0 | 126
19 | 4.6 | 30.5 | 4.1 | 28.8 | 11 | 4.1 | 28.0 | 59 | 4.5 | 27.0 | 133
20 | 4.7 | 30.8 | 4.5 | 29.7 | 12 | 4.6 | 28.5 | 65 | 4.4 | 27.2 | 128
21 | 4.5 | 31.3 | 4.2 | 30.3 | 11 | 4.7 | 29.0 | 65 | 4.4 | 27.5 | 128
22 | 4.7 | 31.3 | 4.4 | 31.0 | 11 | 4.8 | 30.1 | 64 | 4.4 | 28.4 | 123
23 | 4.4 | 32.4 | 4.0 | 31.9 | 10 | 4.6 | 31.1 | 59 | 3.8 | 29.6 | 102
24 | 4.3 | 32.8 | 4.5 | 33.0 | 11 | 4.5 | 31.8 | 57 | 3.8 | 29.3 | 104
25 | 4.3 | 33.6 | 4.2 | 33.8 | 10 | 4.4 | 32.6 | 54 | 3.9 | 29.9 | 104
26 | 4.5 | 34.3 | 4.1 | 33.7 | 10 | 4.7 | 33.2 | 56 | 4.2 | 30.3 | 111
Mean for weeks
1–13 | 4.6 | 24.2 | 4.1 | 23.8 | 14 | 4.3 | 23.0 | 76 | 4.2 | 22.9 | 147
14–26 | 4.5 | 31.0 | 4.2 | 30.3 | 11 | 4.6 | 29.1 | 64 | 4.2 | 27.7 | 124

a Grams of water consumed per animal per day

b Milligrams of sodium bromate consumed per kilogram body weight per day

TABLE H7 Water and Compound Consumption by Male p53 Haploinsufficient Mice in the 43-Week Drinking Water Study of Sodium Bromate

Week | 0 mg/L | | 80 mg/L | | | 400 mg/L | | | 800 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
2 | 3.5 | 25.6 | 3.4 | 25.4 | 10.8 | 3.5 | 25.9 | 53.4 | 3.2 | 24.5 | 103.4
3 | 3.4 | 27.2 | 3.8 | 26.8 | 11.4 | 3.5 | 27.3 | 50.9 | 3.2 | 26.2 | 98.4
5 | 3.5 | 29.2 | 3.6 | 28.7 | 10.0 | 3.5 | 29.5 | 46.8 | 3.4 | 28.5 | 94.5
6 | 3.4 | 30.8 | 3.5 | 29.8 | 9.3 | 3.4 | 30.7 | 44.5 | 3.3 | 29.8 | 87.2
7 | 3.6 | 32.7 | 3.8 | 31.8 | 9.5 | 3.5 | 32.7 | 43.0 | 3.4 | 31.8 | 86.4
8 | 3.5 | 33.7 | 3.5 | 33.0 | 8.6 | 3.5 | 33.9 | 41.6 | 3.2 | 32.8 | 78.0
9 | 3.5 | 34.7 | 3.6 | 33.8 | 8.5 | 3.4 | 33.3 | 40.3 | 3.2 | 33.6 | 76.6
10 | 3.5 | 35.9 | 3.6 | 35.3 | 8.2 | 3.5 | 35.0 | 40.5 | 3.2 | 34.6 | 74.6
11 | 3.4 | 37.2 | 3.6 | 36.7 | 7.9 | 3.5 | 36.7 | 38.7 | 3.0 | 35.2 | 69.2
12 | 3.3 | 38.6 | 3.5 | 36.7 | 7.7 | 3.3 | 37.5 | 35.7 | 3.1 | 36.2 | 69.5
13 | 3.5 | 39.9 | 4.2 | 38.6 | 8.6 | 3.8 | 39.0 | 38.5 | 3.2 | 37.3 | 69.0
14 | 3.3 | 40.6 | 3.8 | 40.0 | 7.6 | 3.5 | 40.0 | 35.3 | 3.1 | 38.3 | 65.6
15 | 3.5 | 42.0 | 3.9 | 41.1 | 7.6 | 3.4 | 41.0 | 33.6 | 3.2 | 39.5 | 65.4
16 | 3.6 | 42.5 | 3.9 | 42.0 | 7.5 | 3.6 | 41.7 | 34.9 | 3.4 | 40.0 | 68.9
17 | 3.8 | 43.6 | 3.9 | 42.8 | 7.4 | 3.7 | 42.4 | 34.8 | 3.4 | 40.5 | 67.1
18 | 3.6 | 44.3 | 4.2 | 44.0 | 7.6 | 3.8 | 43.0 | 35.0 | 3.5 | 41.3 | 68.4
19 | 3.7 | 45.3 | 4.1 | 44.8 | 7.4 | 3.9 | 43.9 | 35.5 | 3.4 | 42.2 | 64.9
20 | 3.6 | 45.8 | 3.9 | 45.1 | 6.9 | 3.9 | 44.3 | 34.9 | 3.4 | 43.0 | 62.9
21 | 3.5 | 46.3 | 3.9 | 45.8 | 6.7 | 3.9 | 44.9 | 34.6 | 3.3 | 43.7 | 61.0
22 | 3.5 | 46.7 | 4.1 | 46.3 | 7.1 | 3.9 | 45.3 | 34.1 | 3.3 | 44.1 | 59.4
23 | 3.4 | 46.8 | 3.8 | 45.9 | 6.6 | 4.0 | 46.0 | 34.4 | 3.3 | 44.8 | 58.5
25 | 1.8 | 47.5 | 2.0 | 47.7 | 3.3 | 2.0 | 47.3 | 16.8 | 1.5 | 46.4 | 26.1
26 | 3.6 | 48.4 | 3.6 | 47.3 | 6.0 | 4.1 | 48.0 | 34.0 | 3.3 | 47.2 | 55.8
27 | 3.7 | 48.1 | 4.0 | 48.1 | 6.7 | 4.1 | 47.8 | 34.0 | 3.2 | 46.7 | 54.3
28 | 3.9 | 49.5 | 3.9 | 49.3 | 6.4 | 4.4 | 48.9 | 36.1 | 3.6 | 47.6 | 60.5
29 | 3.6 | 49.3 | 3.7 | 49.0 | 6.1 | 3.9 | 48.9 | 32.2 | 3.4 | 47.9 | 56.3
30 | 3.6 | 49.5 | 4.0 | 48.4 | 6.6 | 4.1 | 49.0 | 33.8 | 3.5 | 48.2 | 58.9
31 | 3.6 | 49.8 | 3.7 | 47.7 | 6.2 | 4.1 | 49.5 | 33.0 | 3.5 | 48.7 | 57.2
32 | 3.9 | 50.1 | 3.8 | 49.8 | 6.2 | 4.2 | 48.8 | 34.2 | 3.4 | 47.2 | 57.9
33 | 3.6 | 50.4 | 3.8 | 50.2 | 6.0 | 4.1 | 49.6 | 33.3 | 3.4 | 48.6 | 56.2
34 | 3.5 | 50.1 | 3.8 | 50.5 | 6.1 | 4.0 | 48.9 | 33.1 | 3.2 | 48.5 | 52.9
35 | 3.5 | 49.2 | 3.7 | 50.4 | 5.9 | 4.2 | 49.5 | 34.2 | 3.2 | 48.9 | 51.9
36 | 3.8 | 49.6 | 4.0 | 50.8 | 6.4 | 4.2 | 50.1 | 33.5 | 3.2 | 49.5 | 51.8
37 | 4.0 | 50.4 | 3.9 | 50.6 | 6.2 | 4.2 | 50.3 | 33.6 | 3.4 | 50.2 | 54.6
38 | 3.9 | 50.2 | 4.1 | 51.3 | 6.4 | 4.2 | 50.8 | 33.2 | 3.4 | 50.5 | 53.7
39 | 3.9 | 50.2 | 4.1 | 51.4 | 6.3 | 4.1 | 51.0 | 32.4 | 3.3 | 50.5 | 52.1
40 | 4.0 | 50.0 | 4.2 | 52.1 | 6.4 | 4.3 | 51.5 | 33.5 | 3.5 | 51.2 | 54.0
41 | 4.3 | 51.8 | 4.2 | 52.6 | 6.4 | 4.5 | 50.8 | 35.6 | 3.5 | 51.7 | 53.9
42 | 4.1 | 51.4 | 4.3 | 52.5 | 6.5 | 4.7 | 50.9 | 37.2 | 3.4 | 51.2 | 53.2
Mean for weeks
1–13 | 3.5 | 33.2 | 3.6 | 32.4 | 9.1 | 3.5 | 32.9 | 43.1 | 3.2 | 31.9 | 82.4
14–42 | 3.6 | 47.8 | 3.9 | 47.8 | 6.5 | 4.0 | 47.3 | 33.6 | 3.3 | 46.4 | 57.3

a Grams of water consumed per animal per day

b Milligrams of sodium bromate consumed per kilogram body weight per day

TABLE H8 Water and Compound Consumption by Female p53 Haploinsufficient Mice in the 43-Week Drinking Water Study of Sodium Bromate

Week | 0 mg/L | | 80 mg/L | | | 400 mg/L | | | 800 mg/L
Week | Water (g/day)^a^ | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose (mg/kg)^b^ | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
2 | 3.7 | 20.5 | 3.8 | 20.4 | 15.0 | 3.7 | 20.0 | 73.9 | 3.6 | 19.8 | 145.2
3 | 4.5 | 21.2 | 4.2 | 21.6 | 15.6 | 4.0 | 20.7 | 77.4 | 3.7 | 21.1 | 138.9
5 | 4.8 | 22.1 | 4.2 | 23.0 | 14.5 | 4.0 | 22.0 | 72.3 | 4.2 | 22.3 | 149.9
6 | 4.4 | 22.5 | 3.8 | 23.4 | 13.0 | 4.0 | 22.0 | 71.9 | 4.2 | 22.2 | 149.7
7 | 4.4 | 23.1 | 4.3 | 23.9 | 14.3 | 3.9 | 22.4 | 69.1 | 4.0 | 23.0 | 138.5
8 | 4.8 | 23.6 | 4.0 | 24.0 | 13.3 | 3.9 | 22.5 | 69.1 | 4.3 | 23.2 | 147.2
9 | 4.2 | 23.4 | 4.0 | 24.4 | 13.1 | 4.0 | 22.7 | 71.4 | 4.4 | 23.4 | 149.4
10 | 4.5 | 24.2 | 4.2 | 24.6 | 13.7 | 4.2 | 23.3 | 71.9 | 4.1 | 23.9 | 135.7
11 | 4.1 | 24.9 | 4.2 | 25.3 | 13.2 | 4.1 | 23.4 | 69.6 | 4.1 | 24.5 | 135.4
12 | 4.1 | 25.7 | 4.2 | 25.9 | 12.9 | 4.0 | 23.8 | 66.6 | 3.8 | 24.7 | 122.2
13 | 4.6 | 26.4 | 4.2 | 27.0 | 12.4 | 4.3 | 24.7 | 69.5 | 4.3 | 25.4 | 135.1
14 | 4.8 | 27.0 | 4.2 | 27.3 | 12.2 | 4.1 | 24.4 | 67.7 | 4.1 | 25.6 | 127.1
15 | 4.8 | 27.6 | 4.6 | 27.7 | 13.3 | 4.2 | 24.6 | 69.2 | 4.4 | 26.1 | 133.4
16 | 4.8 | 28.8 | 4.5 | 28.5 | 12.6 | 4.2 | 25.3 | 65.9 | 4.0 | 26.9 | 118.5
17 | 4.9 | 29.7 | 4.3 | 29.3 | 11.7 | 4.4 | 25.7 | 68.1 | 4.1 | 27.3 | 121.4
18 | 5.0 | 30.5 | 4.6 | 30.4 | 12.1 | 4.2 | 26.5 | 63.7 | 4.4 | 28.3 | 123.3
19 | 5.1 | 31.1 | 4.3 | 31.5 | 10.8 | 4.3 | 27.1 | 64.2 | 4.1 | 28.7 | 115.0
20 | 4.6 | 31.7 | 4.7 | 32.5 | 11.5 | 4.3 | 27.5 | 62.1 | 4.0 | 28.6 | 112.0
21 | 4.8 | 32.5 | 4.4 | 33.0 | 10.7 | 4.5 | 28.5 | 63.7 | 4.1 | 29.3 | 112.5
22 | 4.7 | 33.2 | 4.3 | 33.4 | 10.3 | 4.3 | 28.3 | 60.2 | 4.1 | 29.9 | 110.1
23 | 4.5 | 33.8 | 4.0 | 33.3 | 9.6 | 4.1 | 29.3 | 56.1 | 3.8 | 30.9 | 98.6
25 | 2.3 | 35.9 | 2.1 | 35.3 | 4.8 | 2.0 | 30.3 | 26.4 | 1.8 | 32.0 | 44.2
26 | 4.7 | 36.6 | 4.6 | 35.4 | 10.5 | 4.1 | 31.5 | 51.6 | 3.9 | 33.1 | 93.2
27 | 4.8 | 37.1 | 4.6 | 37.0 | 9.9 | 4.2 | 31.9 | 52.6 | 4.0 | 33.6 | 94.0
28 | 4.7 | 38.9 | 4.6 | 38.6 | 9.4 | 4.5 | 33.4 | 54.2 | 4.0 | 35.0 | 91.0
29 | 4.7 | 38.5 | 4.4 | 38.8 | 9.1 | 4.1 | 33.5 | 48.9 | 3.8 | 35.3 | 86.8
30 | 4.8 | 39.0 | 4.6 | 39.5 | 9.2 | 4.1 | 33.1 | 50.0 | 4.0 | 36.1 | 87.7
31 | 4.6 | 39.8 | 4.6 | 40.2 | 9.1 | 4.1 | 33.5 | 48.3 | 3.6 | 36.8 | 78.5
32 | 5.2 | 40.7 | 4.7 | 40.5 | 9.2 | 4.5 | 34.9 | 51.3 | 3.8 | 37.0 | 82.9
33 | 4.5 | 41.3 | 4.4 | 41.1 | 8.6 | 4.0 | 35.3 | 45.7 | 3.4 | 36.2 | 74.1
34 | 4.4 | 42.2 | 4.7 | 42.2 | 8.9 | 3.9 | 35.0 | 44.3 | 3.6 | 37.6 | 76.6
35 | 4.2 | 42.4 | 4.4 | 42.7 | 8.3 | 4.1 | 35.9 | 46.1 | 3.5 | 38.0 | 73.8
36 | 4.4 | 43.4 | 4.2 | 43.5 | 7.7 | 4.2 | 36.8 | 45.8 | 3.8 | 39.0 | 78.7
37 | 5.2 | 44.5 | 4.6 | 44.5 | 8.2 | 4.1 | 37.9 | 43.0 | 3.6 | 39.5 | 73.8
38 | 4.4 | 45.2 | 4.9 | 44.0 | 8.8 | 4.1 | 37.6 | 43.9 | 3.7 | 40.5 | 73.5
39 | 4.4 | 44.6 | 4.7 | 44.3 | 8.4 | 4.3 | 37.9 | 45.2 | 3.6 | 40.8 | 70.2
40 | 4.7 | 44.1 | 4.7 | 44.4 | 8.4 | 4.7 | 38.9 | 48.1 | 3.8 | 41.5 | 73.0
41 | 4.5 | 45.0 | 4.7 | 46.1 | 8.1 | 4.2 | 38.9 | 43.6 | 3.7 | 42.2 | 69.4
42 | 4.6 | 47.4 | 4.5 | 46.1 | 7.9 | 4.3 | 38.6 | 45.1 | 3.5 | 42.1 | 66.3
Mean for weeks
1–13 | 4.4 | 23.4 | 4.1 | 24.0 | 13.7 | 4.0 | 22.5 | 71.1 | 4.0 | 23.0 | 140.7
14–42 | 4.6 | 37.6 | 4.4 | 37.5 | 9.6 | 4.1 | 32.2 | 52.7 | 3.8 | 34.2 | 91.4

a Grams of water consumed per animal per day

b Milligrams of sodium bromate consumed per kilogram body weight per day